# REFERENCES

1 Buchbinder R, Blyth FM, March LM, Brooks P, Woolf AD, Hoy DG. Placing the global burden of low back pain in context. Best practice & research Clinical rheumatology. 2013;27(5):575–589.24315140
2 Vassilaki M, Hurwitz EL. Insights in public health: perspectives on pain in the low back and neck: global burden, epidemiology, and management. Hawai’i Journal of Medicine & Public Health. 2014;73(4):122.24765562
3 Deyo RA, Mirza SK, Martin BI. Back pain prevalence and visit rates: estimates from U.S. national surveys, 2002. Spine (Phila Pa 1976). Nov 1 2006;31(23):2724–7. doi:10.1097/01.brs.0000244618.06877.cd 17077742
4 Farley T, Stokke J, Goyal K, DeMicco R. Chronic low back pain: History, symptoms, pain mechanisms, and treatment. Life. 2024;14(7):812.39063567
5 Carey TS, Evans AT, Hadler NM, . Acute severe low back pain. A population-based study of prevalence and care-seeking. Spine (Phila Pa 1976). Feb 1 1996;21(3):339–44. doi:10.1097/00007632-199602010-00018 8742211
6 Discseel. Non Surgical Discseel Spine Procedure. Accessed September 9, 2025. https://discseel.com/
7 Chou R, Deyo R, Friedly J, . Systemic Pharmacologic Therapies for Low Back Pain: A Systematic Review for an American College of Physicians Clinical Practice Guideline. Ann Intern Med. Apr 4 2017;166(7):480–492. doi:10.7326/M16-2458 28192790
8 Pengel LH, Herbert RD, Maher CG, Refshauge KM. Acute low back pain: systematic review of its prognosis. BMJ. Aug 9 2003;327(7410):323. doi:10.1136/bmj.327.7410.323 12907487
9 Chou R, Deyo R, Friedly J, . Nonpharmacologic Therapies for Low Back Pain: A Systematic Review for an American College of Physicians Clinical Practice Guideline. Ann Intern Med. Apr 4 2017;166(7):493–505. doi:10.7326/M16-2459 28192793
10 Chou R, Deyo R, Friedly J, . Noninvasive Treatments for Low Back Pain. Noninvasive Treatments for Low Back Pain. 2016. AHRQ Comparative Effectiveness Reviews. https://www.ncbi.nlm.nih.gov/pubmed/26985522
11 Ibrahim T, Tleyjeh IM, Gabbar O. Surgical versus non-surgical treatment of chronic low back pain: a meta-analysis of randomised trials. Int Orthop. Feb 2008;32(1):107–13. doi:10.1007/s00264-006-0269-6 17119962
12 Weinstein JN, Tosteson TD, Lurie JD, . Surgical versus nonsurgical therapy for lumbar spinal stenosis. N Engl J Med. Feb 21 2008;358(8):794–810. doi:10.1056/NEJMoa0707136 18287602
13 Pauza K, Boachie-Adjei K, Nguyen JT, . Long-term Investigation of Annulargrams and Intra-annular Fibrin to Treat Chronic Discogenic Low Back Pain and Radiculopathy: 1-, 2-, and 3-Year Outcome Comparisons of Patients with and without Prior Surgery. Pain physician. 2024;27(8):537–553.39621982
14 Yin W, Pauza K, Olan WJ, Doerzbacher JF, Thorne KJ. Intradiscal injection of fibrin sealant for the treatment of symptomatic lumbar internal disc disruption: results of a prospective multicenter pilot study with 24-month follow-up. Pain Med. Jan 2014;15(1):16–31. doi:10.1111/pme.12249 24152079
15 Moola S MZ, Tufanaru C, Aromataris E, Sears K, Sfetcu R, Currie M, Qureshi R, Mattis P, Lisy K, Mu P-F. Chapter 7: Systematic reviews of etiology and risk. In: Aromataris E MZ, ed. JBI Manual for Evidence Synthesis. JBI; 2020. https://synthesismanual.jbi.global
16 Guyatt G, Oxman AD, Akl EA, . GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. Apr 2011;64(4):383–94. doi:10.1016/j.jclinepi.2010.04.026 21195583
17 Spinal Restoration Inc. Treatment of Symptomatic Lumbar Internal Disc Disruption (IDD) With the Biostat® System. Updated 05/16/2014. Accessed August 7, 2025. https://clinicaltrials.gov/study/NCT01011816
18 Ju DG, Kanim LE, Bae HW. Is There Clinical Improvement Associated With Intradiscal Therapies? A Comparison Across Randomized Controlled Studies. Journal article. Global Spine J. Jun 2022;12(5):756–764. doi:10.1177/2192568220963058 33047622
19 Dettori JR. Loss to follow-up. Evid Based Spine Care J. Feb 2011;2(1):7–10. doi:10.1055/s-0030-1267080
20 Mazor KM, Clauser BE, Field T, Yood RA, Gurwitz JH. A demonstration of the impact of response bias on the results of patient satisfaction surveys. Health Serv Res. Oct 2002;37(5):1403–17. doi:10.1111/1475-6773.11194 12479503
21 Djuric N, Spoor JKH, Schroder RD, Akker E, Emons JAM, Dammers R. Anaphylaxis associated with Tisseel fibrin sealant during re-resection of a craniopharyngioma: illustrative case. J Neurosurg Case Lessons. Jun 2 2025;9(22)doi:10.3171/CASE2517