# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich-Nelson for literature searching, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Timothy Dawson, MD
  Deputy Executive Director
  Pain Management Opioid Safety and Prescription Drug Monitoring Program (PMOP)

- Ricardo Roa, MD
  Senior Medical Advisor
  Office of Integrated Veteran Care, Clinical Determinations Unit (CDU)