# Executive Summary

KEY FINDINGS

► BIOSTAT BIOLOGX Fibrin Intradiscal Injection
  - In adults with chronic discogenic low back pain, fibrin intra-discal injection using the BIOSTAT BIOLOGX intra-discal system does not decrease pain intensity or pain interference (moderate to low certainty of evidence [COE]).
  - Serious adverse events as well as any adverse events are common with fibrin intra-discal injection and may not differ between fibrin and saline (low COE).
  - Results are derived from individuals with chronic discogenic pain who failed prior nonsurgical interventions and had a positive provocative discogram. Data include: 1) a single small (N = 15) pre-post study; 2) 1 unpublished randomized controlled trial (RCT) versus saline (N = 220) identified only on clinicaltrials.gov; and 3) a review from authors reporting longer-term results from their single site (N = 13) of the multisite RCT.
► Discseel Intra-Annular Fibrin Injection System
  - In adults with chronic low back pain the evidence is very uncertain regarding the effectiveness and harms of the intra-annular Discseel fibrin injection system.
  - Data are limited to 1 pre-post study from a single clinician among symptomatic individuals with reported outcomes of those undergoing the procedure limited to those who completed both baseline and follow-up measures (a minority of the entire cohort). All individuals had failed prior interventions and were noted to have multilevel lumbar spine “annular leaks” on diagnostic Annulargram.
  - No data exist for the Discseel procedure in adults with cervical neck pain.

## CURRENT REVIEW

In response to a request from the Veterans Health Administration (VHA) Office of Integrated Veteran Care Clinical Determinations Unit (CDU) and the Pain Management Opioid Safety and Prescription Drug Monitoring Program (PMOP), we conducted a systematic review on the efficacy and safety of fibrin intervertebral injections (eg, Discseel). This review will be used to inform development of a Clinical Determination and Indication (CDI) document to help community clinicians and VHA staff determine if a Veteran meets the clinical criteria for this, or similar, procedures.

With input from key stakeholders within VHA and members of a technical expert panel, the following key questions were the focus of this review:

- Key Question 1 (KQ1): Among adults with back or neck pain, what is the efficacy and safety of fibrin intervertebral injections?
  ○ Key Question 1a (KQ1a): Does efficacy and safety of fibrin intervertebral injections vary based on patient and condition characteristics?

To identify articles relevant to the key questions, a research librarian searched MEDLINE (Ovid), CDSR and CENTRAL via Cochrane Library (Wiley), and Scopus (Elsevier) through June 26, 2025, using terms related to back and neck pain. Using pre-specified criteria, full-text articles were independently screened by 2 reviewers, requiring consensus for inclusion or exclusion. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus. Certainty of evidence was conducted via team consensus for the following outcomes: pain intensity, pain interference, quality of life, and adverse events.

Our search did not identify any published RCTs or comparative observational studies of fibrin intervertebral injections. As determined a priori, since no published comparative studies were identified, we evaluated uncontrolled studies and trial registrations.

We identified 4 records of interest, describing 3 unique studies: 2 uncontrolled, single site case series, 1 randomized trial registration on clinicaltrials.gov without published results, and a review article which provides results from a single site of the multisite randomized trial registered on clinicaltrials.gov. Three of these publications evaluated the effects of the BIOSTAT BIOLOGX system. One publication reported on the Discseel Intra-Annular Fibrin Injection.

### BIOSTAT BIOLOGX Fibrin Intra-Discal Injection

A small, uncontrolled, 3-center pilot study (N = 15) evaluated the effectiveness of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device. Mean low back pain intensity (measured with the Visual Analog Scale [VAS]) and pain interference (measured with the Roland-Morris Disability Questionnaire [RMDQ]) scores decreased from baseline at the primary evaluation period of 26 weeks, with clinically significant pain relief and disability reduction (>30% reduction) occurring in 86.7% (13/15) and 73.3% (11/15) of subjects at the 26-week period. Findings generally persisted through 104 weeks. Adverse events occurred in 67% (9/15) of participants.

Based in part on results from this small pilot case series, a multisite randomized controlled trial was initiated (N = 220) and registered on clinicaltrials.gov (NCT01011816 (https://clinicaltrials.gov/study/NCT01011816)) with an initial estimated enrollment of 260. Contrary to the pilot study, this trial was stopped prior to the last subject’s last extended follow-up visit at 78 weeks, due to lack of efficacy at the primary study endpoint (26 weeks). At 26 weeks there was no difference in the primary study outcome of “subject success based on a composite of a minimum 30% decrease in low back pain, 30% improvement in function, maintenance of neurological status, no secondary interventions, and no serious adverse events” of BIOSTAT BIOLOGX Fibrin compared with saline, though point estimates for success favored saline. There was also no difference in the percentage of subjects achieving a 30% decrease in pain intensity from baseline (measured with VAS; moderate COE) or percentage of subjects achieving a minimum 30% decrease in pain interference (measured with RMDQ; low COE). There may be little to no difference in serious adverse events, as they were common in both groups (including back pain; low COE).

We also identified 1 review article which published single site results of this 14-center trial (N = 13).

### Discseel Intra-Annular Fibrin Injection

We identified 1 uncontrolled, single site case series (N = 827) evaluating the effectiveness of Discseel proprietary fibrin intervertebral injection products, system, and processes for low back pain compared with baseline at up to 3 years after treatment. Outcomes reported included pain intensity via the VAS, pain interference via the Oswestry Disability Index (ODI), quality of life via the EuroQoL, and serious adverse events. Evidence was insufficient for all reported outcomes. While authors noted an improvement in VAS, ODI, and EuroQoL from baseline through 36 months, analyses were limited to the minority of participants that provided survey responses at baseline and follow-up time points. Authors stated that “there were no serious adverse events recorded throughout the study,” though no other information, including definition of serious adverse events, was provided.

The concept of fibrin injection to seal disc tears and leaks with subsequent tissue healing is appealing, especially given the burden of low back pain. Future research should consist of large, multicenter double-blinded randomized controlled trials of individuals with chronic back and neck pain with specified inclusion and exclusion criteria and providing long-term (≥1 year) outcomes.

## CONCLUSIONS

Evidence regarding fibrin injections for back pain is limited in quality and quantity. There are no data for individuals with neck pain. However, fibrin injection using the BIOSTAT BIOLOGX intra-disc system does not reduce pain severity or interference versus saline injection in adults with chronic low back discogenic pain who failed prior nonsurgical interventions. Both fibrin and saline injections resulted in frequent and serious adverse events. Evidence is very uncertain regarding benefits and harms of the Discseel Intra-Annular Fibrin Injection System in individuals with low back pain who failed prior interventions including surgery. Individuals had annular tears based on a diagnostic Annulargram, for which diagnostic accuracy is unknown. Findings come from a single center, single investigator, pre-post report from the company founder and are limited to the minority of subjects who underwent the procedure and also completed both baseline and follow-up surveys. Applicability of findings to different fibrin injection systems/solutions, diagnostic criteria, individuals, or clinicians outside of these study settings is unknown. Prior to widespread implementation, evidence of effectiveness from randomized controlled trials of fibrin injection for back and neck pain are needed, especially evaluating the Discseel Intra-Annular Fibrin Injection System.