# DISCUSSION

## KEY FINDINGS

### BIOSTAT BIOLOGX Fibrin Intra-Discal Injection

- In adults with chronic discogenic low back pain, fibrin intra-discal injection using the BIOSTAT BIOLOGX intra-disc system does not decrease pain intensity or pain interference (moderate to low COE) compared with intra-disc saline injection.
  ○ BIOSTAT BIOLOGX intra-disc system compared with intra-disc saline injection also did not improve the primary study outcome (and the study was terminated early), which was a composite measure of decrease in low back pain, improvement in function, maintenance of neurological status, no secondary interventions, and no serious adverse events at 26 weeks follow-up.
- Serious adverse events as well as any adverse events are common with fibrin intra-discal injection and may not differ between fibrin and saline (low COE).
- Results are derived from individuals with chronic discogenic pain who had failed prior nonsurgical interventions and had a positive provocative discogram. Data are limited and consist of: 1) a single small (N = 15) pilot pre-post study; 2) 1 unpublished RCT versus saline (N = 220) identified only on clinicaltrials.gov; and 3) a published review from authors reporting longer-term results from their single site (N = 13) of the multisite randomized trial.

### Discseel Intra-Annular Fibrin Injection System

- In adults with chronic low back pain, the evidence is very uncertain regarding the effectiveness and harms of the intra-annular Discseel fibrin injection system.
  ○ Data are limited to 1 pre-post study among symptomatic individuals who failed prior interventions, were noted to have multilevel lumbar spine “annular leaks” on diagnostic Annulargram, and were injected with a fibrin mixture using the Discseel fibrin intervertebral injection system.
  ○ Harms reporting was limited to authors’ statement: “there were no serious adverse events recorded throughout the study” without definition of serious adverse events.
- There are no data for the Discseel fibrin procedure in adults with cervical neck pain.

Our systematic review of interventions employing fibrin injection for the treatment of chronic neck and back pain was limited in the quantity and quality of available evidence and focused on 2 proprietary injection systems used in different populations and based on different diagnostic and treatment. One employed fibrin injection directly into a single level disc of adults who had discogenic pain identified on physical and clinical examination and subsequently underwent discography that reproduced their pain symptoms.^14,17^ Patients with prior back surgery were excluded. A small pilot pre-post report suggested a benefit. However, a subsequent multicenter RCT of this approach was discontinued early for failure to show benefit versus intra-discal saline injections, highlighting the limits of unblinded pre-post studies in pain treatments. Adverse events and serious adverse events were common. Subsequently, the same author of the intra-disc fibrin procedure developed another method of fibrin spinal injection using a modified diagnostic and delivery system that injected fibrin into the annular fibrosis of individuals with chronic low back pain.^13^ This single center, single investigator, pre-post study reported on participants who first underwent a diagnostic proprietary Annulargram, had multilevel annular tears with imaging evidence of leaks, agreed to receive the intervention, and who subsequently completed baseline and follow-up surveys. No other data exist on this procedure.

In the case of the intra-discal injection, a small pilot pre-post study reported large and clinically meaningful improvements in pain and function.^14^ However, the follow-up larger multicenter double-blind randomized trial designed to accurately assess effectiveness and harms was stopped early for lack of efficacy for their primary outcome at 26 weeks and evidence that fibrin injection did not improve pain severity or pain interference compared with saline injection.^17^ Frequent and serious adverse events occurred in both groups, indicating that intra-discal injection with either fibrin or saline causes harm. Furthermore, the null findings from the double-blind comparative RCT strongly refute the pre-post findings from the small pilot study. These contradictory findings highlight limitations in assessing pain outcomes through unblinded and pre-post studies, emphasizing the importance of blinded RCTs.

The Biologx intra-disc injection study authors^14,17^ hypothesized that injection into the annular fibrosis with a new and unvalidated diagnostic (Annulargram) and treatment approach (Discseel Intra-Annular Fibrin Injection System) would be effective and safe.^13^ The authors conducted and published results from a pre-post study based at a single center specialized, single-interventionalist pain management institute. The study reported improvement from baseline pain and disability through 3 years in the subgroup of individuals who completed questionnaires (less than 50% of the entire original cohort). The authors reported “no infections or other serious adverse events were recorded throughout the study,” without explicitly defining serious adverse events. A major limitation, beyond the lack of randomization, blinding, or comparator group is that the paper only provides follow-up data on patients who completed pain and functional status surveys. This was less than 50% of all individuals undergoing the procedure at all time points. No information was provided on “nonserious” adverse events that could be important harms, particularly as the procedure involves placement of a 22-gauge trocar with steel stylet into multiple intra-vertebral discs. No data were reported on those undergoing Annulargrams who did not have evidence of annular leaks.

There are a number of methodological limitations in this study. As mentioned above, findings from unblinded pre-post comparisons are at high risk of bias for assessing outcomes. In the case series by Pauza,^13^ outcomes reporting is problematic in that results are only provided for individuals who completed the outcome measures survey (response bias). As fewer than 50% of participants who completed the intervention provided data for any of the follow-up time points, nor were statistical methods (ie, imputation) used to address the data missingness, the reported analyses are subject to bias. Investigation into reasons for loss to follow-up or lack of participation would be useful in understanding if those that declined study participation at follow-up time points were experiencing poorer outcomes. Previous research has demonstrated that satisfied patients are more likely to respond and have better outcomes than nonresponders.^20^ Thus, reported outcomes are, at best, optimistic of the full cohort. The authors also do not provide information on the number of individuals who were deemed eligible for the procedure but did not agree to have the procedure or provide information on those who had an Annulargram but did not have evidence of annular tears or fluid leak.

The use of the Annulargram as the diagnostic tool/method to identify eligible participants is concerning and without prior information on diagnostic accuracy. The authors provide no information on the diagnostic accuracy of this test, including the number of individuals who underwent Annulargrams but did not have evidence of leaks. The Annulargram and subsequent fibrin procedure has only been conducted at a single center and by a single individual who is the company founder. It is not known how results would apply to other centers, clinicians, or patients. Additionally, the procedure is stated to be used for patients with neck pain, but there are no data on either the diagnostic accuracy or benefits and harms of Annulargrams in patients with neck pain. We concluded that evidence was insufficient for both benefits and harms due to critical study limitations including lack of blinding, no control group, and incomplete outcome reporting. The lead author of the Discseel paper is the founder of the company and created the term “leaky disc syndrome,” which he now classifies as a condition causing the patient’s symptoms, thus creating the need for the treatment that he developed. Furthermore, the lead author developed and patented both the diagnostic Annulargram and subsequent injection procedure. He also is listed as personally funding this investigation. Thus, important financial conflicts of interest exist, despite the publication’s statement: “Each author certifies that he or she, or a member of his or her immediate family, has no commercial association (i.e., consultancies, stock ownership, equity interest, patent/licensing arrangements, etc.) that might pose a conflict of interest in connection with the submitted manuscript.” Few individuals in the United States are listed as providing the procedure, and there are no data on these providers’ results.^6^ While the Discseel website notes the procedure is available for individuals with neck pain or chronic back pain with no obvious etiology, none of the individuals included in the single report by Pauza^13^ had neck pain; all had chronic lumbar pain failing prior interventions including surgery and all had annular tears.

## APPLICABILITY OF FINDINGS

Chronic back pain is common and disabling. Many treatment options exist but often are unsuccessful, have important harms, or patients are not candidates for or do not desire available options. Thus additional, less invasive, effective approaches would be useful. Patient clinical history, study exclusion and inclusion criteria, the device and fibrin composition utilized, the injection location as well as the administration of interventions in these studies varied considerably. Thus, while both use fibrin as a sealant for treatment of back pain, we reported findings separately by the population enrolled and procedure/system utilized. For example, the intra-discal fibrin (BIOSTAT BIOLOGX) procedure limited inclusion to individuals with single level, primarily axial discogenic pain who had failed prior therapies. Individuals were excluded if they had undergone prior surgical interventions or had evidence of radicular pain. Patients in the intra-annular fibrin injection (Discseel) cohort were included if they had prior lumbar surgery or radiculopathy, but they had to have failed at least 1 and perhaps as many as 4 prior invasive procedures. Fibrin and precursor composition appeared to vary as did devices, with both the intra-articular and the intra-discal procedures and fibrin being patented and proprietary. The results from the intra-annular cohort are also based on a single institutional unblinded-pre-post study from a single investigator who is the founder of the company and rely on the minority subset of individuals who underwent the procedure and completed baseline and follow-up outcome measure surveys. There are no data to assess whether results would vary if implemented by other proceduralists. Importantly, the selection criteria and intervention details for the Discseel intra-annular injection are not well defined. It is not known how many individuals had Annulargrams but were not included in the study either because they did not identify annular tears or due to complications, and they did not undergo fibrin injection. The subjects’ mean age was under 60 years and BMI was <30. There was no information on Veteran status, though no VA medical centers participated. Furthermore, the fibrin substance used in these studies is proprietary and comprised of substances in addition to fibrin. Composition, volume, and delivery of fibrin sealant differed in the intra-disc and intra-annular studies.

## LIMITATIONS

As noted above, the limitations in our findings are primarily related to the limits in the amount and quality of published information. For the intra-disc procedure (BIOSTAT BIOLOGX), a single unpublished randomized trial with limited information available on clinicaltrials.gov found that intra-disc fibrin injection did not improve pain severity or interference and resulted in frequent and often serious adverse events, despite a small pre-post study suggesting benefit. The same author of this intra-discal procedure notes the harms and lack of effectiveness for this procedure and indication. They subsequently published a single center pre-post study and claimed effectiveness, without noting the previously mentioned methodological limitations of an unblinded uncontrolled report for their intra-disc procedure with results refuted in a subsequent RCT. Finally, patients were highly selected for inclusion in these studies and interventions were provided by a very limited group of trained clinicians. Few individuals are trained and certified in the procedure, and even when trained individuals carry out the procedure, it is unlikely that their results would equal published results.

## IMPLICATIONS FOR POLICY

This report was conducted independently by the Minneapolis VA ESP Center using standard and validated systematic review methods at the request of the Veterans Health Administration Office of Integrated Veteran Care Clinical Determinations Unit and the Pain Management Opioid Safety and Prescription Drug Monitoring Program. Our ESP Center discussed the key clinical questions, populations, interventions, and outcomes of interest with our nominating partners and developed and received approval of a preregistered review protocol. Our systematic review on the efficacy and safety of fibrin intervertebral injections included identified patient clinical conditions; diagnostic procedures (discogram or Annulargram); fibrin injection volumes; compositions; procedure systems; injection locations (single intra-disc vs multiple intra-annular); and patient outcomes (axial nonradicular pain with exclusion of prior surgery vs inclusion of patients undergoing prior surgery even for radicular pain). Our inclusion decisions were made to provide available evidence on any fibrin-based “sealant” procedure for adults with chronic back or neck pain. The results of this review will be used to help inform development of a Clinical Determination and Indication to assist community clinicians and VA staff in determining if the procedures are effective and safe and if a Veteran and clinician meets the criteria for these procedures.

## FUTURE RESEARCH

The concept of fibrin injection to seal disc tears and leaks with subsequent tissue healing is appealing, especially given the burden of low back pain. Future research should consist of the following, especially for the inter-annular procedure: large, multicenter double-blinded randomized controlled trials of individuals with chronic back pain with specified inclusion and exclusion criteria and providing long-term (≥1 year) outcomes. Separate trials (or subgroup analyses) of individuals with chronic neck pain are also needed, as benefits and harms in patients with neck pain may differ from those with lower back pain. Studies are needed to understand the etiology and veracity of the newly coined “leaky disc syndrome,” whether this truly corresponds to identified pain and dysfunction, and whether intervening on such leaks results in clinically important benefits with acceptable harms. If so, in which individuals? How important is clinician training? Are Annulargrams necessary for diagnosis, as they are invasive and potentially harmful? It is not known if “leaky disc syndrome” occurs in asymptomatic individuals or the diagnostic accuracy of Annulargrams in patients with low back and neck pain that may result from other etiologies. Authors noted that imaging tests such as MRI scans are inadequate for detecting “leaky disc syndrome,” so it is unclear what clinical and diagnostic criteria could reliably be used to refer potentially eligible individuals for additional evaluation. Many asymptomatic individuals have herniated or bulging discs. They may develop low back or neck pain, be found to have imaging-related disc pathology upon imaging, have their symptoms attributed to disc disease, and thus be recommended for intervention. It is likely that similar clinical scenarios exist for individuals’ tears identified on Annulargrams. Specifically, information is needed on the diagnostic accuracy (and harms) of Annulargrams in individuals suspected of “leaky disc syndrome.” This includes assessing harms, burden, and costs among individuals who undergo Annulargrams but are found not to have tears.

## CONCLUSIONS

Evidence regarding fibrin injections for back pain is limited in quality and quantity. There are no data for individuals with neck pain. However, fibrin injection using the BIOSTAT BIOLOGX intra-disc system does not reduce pain severity or interference versus saline injection in adults with chronic low back discogenic pain who failed prior nonsurgical interventions. Both fibrin and saline injections resulted in frequent and serious adverse events. Evidence is very uncertain regarding benefits and harms of the Discseel Intra-Annular Fibrin Injection System in individuals with low back pain who failed prior interventions including surgery. Individuals had annular tears based on a diagnostic Annulargram, for which diagnostic accuracy is unknown. Findings come from a single center, single investigator, pre-post report from the company founder and are limited to the minority of subjects who underwent the procedure and also completed both baseline and follow-up surveys. Applicability of findings to different fibrin injection systems/solutions, diagnostic criteria, individuals, or clinicians outside of these study settings is unknown. Prior to widespread implementation, evidence of effectiveness from randomized controlled trials of fibrin injection for back and neck pain are needed. especially evaluating the Discseel Intra-Annular Fibrin Injection System.