# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW

Our search did not identify any published randomized controlled trials (RCTs) or comparative observational studies of fibrin intervertebral injections. As determined a priori, since no published comparative studies were identified, we evaluated uncontrolled studies and trial registrations.

We identified 4 records of interest, describing 3 unique studies: 2 uncontrolled, single site case series,^13,14^ 1 randomized trial registration on clinicaltrials.gov without published results,^17^ and a review article which provides results from a single site of the multisite randomized trial registered on clinicaltrials.gov.^18^ Three of these publications evaluated the effects of the BIOSTAT BIOLOGX system.^14,17,18^ Characteristics and outcomes of these studies can be found in Table 1, and certainty of evidence ratings are shown in Table 2. One publication reported on the Discseel Intra-Annular Fibrin Injection^13^; characteristics and outcomes of this study can be found in Table 3, and certainty of evidence ratings are given in Table 4.

## FINDINGS

### BIOSTAT BIOLOGX Fibrin Intra-Discal Injection

A small, uncontrolled, 3-center pilot study (N = 15; Yin, 2014) evaluated the effectiveness of a BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device.^14^ This system injected the fibrin resorbable mixture (up to 4 mL) into 1 (N = 12) or 2 (N = 3) lumbar discs. The sample included participants with chronic (>6 months) primarily axial, noncompressive (without radicular pain), symptomatic single or 2-level lumbar discogenic pain (internal disc disruption) as diagnosed with pressure- and volume-controlled provocation discography. Individuals were unresponsive to at least 6 weeks of nonoperative treatment including epidural steroid injections and medial nerve branch block or facet joint injection. Patients could not have undergone prior lumbar surgery, invasive disc procedures at the affected level, had central spinal stenosis symptoms, or had pain at more than 2 lumbar vertebrae. The study assessed pain intensity via the Visual Analog Scale (VAS) (0-100 scale with 100 being the worst pain), pain interference via the Roland-Morris Disability Questionnaire (RMDQ) (0-24 scale with 24 indicating maximum disability), quality of life via the EuroQol EQ-5D, and adverse events up to 104 weeks after treatment. Mean low back pain VAS and RMDQ scores at baseline decreased at the primary evaluation period of 26 weeks, with clinically significant pain relief and disability reduction (>30% reduction) occurring in 86.7% (13/15) and 73.3% (11/15) of subjects at the 26-week period. Findings generally persisted through 104 weeks. The percentage of individuals taking opioids for back pain was lower at the 26-week time point (64.3%; 9/15) than at baseline (80%; 12/15). Adverse events occurred in 9 (67%) of subjects (Table 1).

Based in part on results from the small pilot case series report by Yin, a multisite randomized controlled trial was initiated (N = 220; Pauza, 2014) and registered on clinicaltrials.gov (NCT01011816 (https://clinicaltrials.gov/study/NCT01011816)) with an initial estimated enrollment of 260.^17^ This double-blinded RCT investigated the effects of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device, compared with a saline injection also using the Biostat Delivery Device (rated some concerns risk of bias) injected into a single lumbar intervertebral disc (64% were treated at the L5/S1 level). As no peer-reviewed published results for this entire trial were identified, we abstracted the results for this trial that were posted on clinicaltrials.gov. This trial was stopped prior to the last subject’s last extended follow-up visit at 78 weeks, due to lack of efficacy at the primary study endpoint (26 weeks).^17^ Additional longer-term outcomes were to be VAS scores for low back pain and RMDQ scores at 39, 52, and 78 weeks follow-up. Patients were mostly aged ≤60 years, 90% were White race, there was a near equal distribution of males and females, and the mean BMI was 27.9 kg/m^2^. Baseline opioid medication was used in 146/220; (66.4%), though no information on post intervention opioid or pain medication use was provided. Ten participants (5 each in the BIOSTAT BIOLOGX Fibrin and saline group) did not receive the injection per protocol due to subject discomfort or investigator discretion.^17^

At 26 weeks there was no difference in the primary study outcome of “subject success based on a composite of a minimum 30% decrease in low back pain, 30% improvement in function, maintenance of neurological status, no secondary interventions, and no serious adverse events” of BIOSTAT BIOLOGX Fibrin compared with saline, though point estimates for success favored saline (33.5% vs 39.3%; p = 0.52; absolute risk difference [ARD] = −5.8%; 95% CI [5.0%, −8.8%]; risk ratio [RR] = 0.85; 95% CI [0.42, 1.46]). There was also no difference in the percentage of subjects achieving a 30% decrease in pain intensity from baseline (42.1% vs 50.0%; RR = 0.84; 95% CI [0.6, 1.2]; p = 0.35) or percentage of subjects achieving a minimum 30% decrease in Roland-Morris Disability Questionnaire score (52.4% vs 50.0%; RR = 1.05; 95% CI [0.8, 1.4]; p = 0.76).^17^

No deaths were reported. Serious adverse events were common in both groups (13.4% and 12.5%; p = 1.0; BIOSTAT BIOLOGX and saline, respectively). Additional adverse events (excluding serious) were common in both groups, occurring in 29.9% and 19.6%, respectively, among those randomized to BIOSTAT BIOLOGX or saline (p = 0.17; RR = 1.52; 95% CI [0.83, 2.65]). Adverse events included back pain in 12.2% versus 5.4% and pain in extremity in 9.8% versus 5.4% for injection with fibrin or saline, respectively (p > 0.2 for both outcomes; Table 1).^17^

We identified 1 review article which published single site results of this 14-center trial (N = 13; 10 patients injected with BIOSTAT BIOLOGX, 3 with saline) representing 5.9% of all those randomized in the parent study.^18^ We report their findings of outcome follow-up periods not available in the full RCT for completeness of data presentation, although findings may not be fully representative of the entire trial. Authors reported that patients at their site who received saline injection had significantly greater reduction in pain intensity at 6, 12, and 24 months compared with fibrin (p < 0.05 at all time points). There were no statistically significant differences at 6, 12 or 24 months in RMDQ scores (though effects favored saline [p > 0.05]).

Table 1 Key Characteristics and Outcomes of BIOSTAT BIOLOGIX Studies

Study; Study Design | Population | Intervention Characteristics | Comparator | Outcomes Assessed; Mean (SD)
Yin, 2014 ^14^; Uncontrolled single site case series; N = 15 | “Intractable axial (without radicular pain or radiculopathy) lower back pain (≥6months), single, or contiguous two-level lumbar discogenic pain confirmed through meticulous provocation discography”; Mean age (SD): 43.9 (10.7); Female: 47%; Previous back surgery: patients excluded if prior back surgery | Volume- and pressure-controlled intra-discal delivery of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device | Pre-post comparison | Pain Intensity (VAS, back); Baseline: 72.4 (14.2); 26 weeks: 31.7 (26.0); MD = −40.7 (7.1) (p = NR); 52 weeks: 35.4 (29.3); MD = −37.3 (8.4) (p = NR); 104 weeks: 33.0 (24.8); MD = −38.5 (9.5) (p = NR)
Yin, 2014 ^14^; Uncontrolled single site case series; N = 15 | | Volume- and pressure-controlled intra-discal delivery of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device | Pre-post comparison | Pain Interference (RMDQ); Baseline: 15.2 (4.5); 26 weeks: 8.9 (6.5); MD = −6.3 (6.1) (p = NR); 52 weeks: 6.2 (4.7); MD = −9.0 (5.6) (p = NR); 104 weeks: 5.6 (4.1); MD = −9.5 (5.6) (p = NR)
Yin, 2014 ^14^; Uncontrolled single site case series; N = 15 | | Volume- and pressure-controlled intra-discal delivery of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device | Pre-post comparison | Quality of Life (EuroQoL); Baseline: 0.48 (0.19); 26 weeks: 0.64 (0.25); 52 weeks: 0.72 (0.21); 104 weeks: 0.74 (0.20)
Yin, 2014 ^14^; Uncontrolled single site case series; N = 15 | | Volume- and pressure-controlled intra-discal delivery of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device | Pre-post comparison | Medication for Back Pain: Opioids (N, %); Baseline: 12 (80.0); 26 weeks: 10 (66.7); 52 weeks: 9 (69.2); 104 weeks: 6 (54.5)
Yin, 2014 ^14^; Uncontrolled single site case series; N = 15 | | Volume- and pressure-controlled intra-discal delivery of BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device | Pre-post comparison | Adverse Events; “Adverse events were reported in nine subjects. Two instances of low back muscle spasm and one case of discitis were the only events considered related to the procedure or product.” Two of the adverse events were considered serious.
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Pain Intensity (VAS, back; % achieving ≥30% decrease in pain from baseline); Fibrin: 69/164 (42.1%); Saline: 28/56 (50.0%); RR = 0.84 (0.6, 1.2)^a^; p = 0.35^a^
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Pain Interference (RMDQ; % achieving ≥30% decrease in pain from baseline); Fibrin: 86/164 (52.4%); Saline: 28/56 (50.0%); RR = 1.05 (0.8, 1.4)^a^; p = 0.76^a^
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Overall Serious AE (N, %) ^b^; Fibrin: 22/164 (13.4); Saline: 7/56 (12.5); RR = 1.07 (0.5, 2.4)^a^; p = 1.0^a^
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Back Pain as Serious AE (N, %) ^b^; Fibrin: 6/164 (3.7); Saline: 1/56 (1.8); RR = 2.04 (0.3, 16.7)^a^; p = 0.68^a^
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Overall AE (not including serious) (N, %); Fibrin: 49/164 (29.9); Saline: 11/56 (19.6); RR = 1.05 (0.9, 2.7)^a^; p = 0.76^a^
Pauza, 2014 ^17^; RCT Registration NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1&tab=results); N = 220 | Fibrin:; N = 164; Mean age (SD): 39.7 (10.7); Female: 50.6%; Previous back surgery: 1.9%; Saline:; N = 56; Mean age (SD): 41.9 (11.4); Female: 57.1%; Previous back surgery: 1.8% | 1 injection of up to 4 mL of BIOSTAT BIOLOGX Fibrin Sealant into a single lumbar intervertebral disc using the Biostat Delivery Device | 1 injection of up to 4 mL of saline solution into a single lumbar intervertebral disc using the Biostat Delivery Device | Back Pain as AE (not including serious) (N, %); Fibrin: 20/164 (12.2); Saline: 3/56 (5.4); RR = 2.3 (0.7, 7.4)^a^; p = 0.21^a^

Notes.

a Calculated by evidence review team;

b “An adverse event that results in death, is life threatening, requires inpatient hospitalization or extends a current hospital stay, results in an ongoing or significant incapacity or interferes substantially with normal life functions, or causes a congenital anomaly or birth defect. Medical events that do not result in death, are not life threatening, or do not require hospitalization may be considered serious adverse events if they put the participant in danger or require medical or surgical intervention to prevent one of the results listed above.”

Abbreviations. MD=mean difference; NR=not reported; RMDQ=Roland-Morris Disability Questionnaire; RR=risk ratio; SD=standard deviation; VAS=Visual Analog Scale.

Table 2 Summary of Evidence for BIOSTAT BIOLOGIX

Outcome | Studies (Participants) | Measure | Summary of Findings | Certainty of Evidence
Pain Intensity | 1 RCT (220)^17^ | VAS; (% achieving ≥30% decrease in back pain from baseline) | Fibrin: 69/164 (42.1%); Saline: 28/56 (50.0%); RR = 0.84 (0.6, 1.2); p = 0.35 | ⨁⨁⨁◯^a^ Moderate; There is probably little to no difference in reducing back pain with fibrin injections compared with saline injections.
Pain Interference | 1 RCT (220)^17^ | RMDQ; (% achieving ≥30% decrease in pain from baseline) | Fibrin: 86/164 (52.4%); Saline: 28/56 (50.0%); RR = 1.05 (0.8, 1.4); p = 0.76 | ⨁⨁◯◯^a,b^ Low; There is probably little to no difference in reducing pain interference with fibrin injections compared with saline injections.
Quality of Life | 1 uncontrolled observational^14^ (15) | EuroQol EQ-5D | Pre-post comparisons; reported improvements but no statistical test provided. Authors stated; “…demonstrated improvements in the subjects’ conditions, although the small number of subjects enrolled preclude definitive determination of efficacy.” | ⨁◯◯◯^a,c^ Insufficient; The effect of fibrin injections on quality of life is very uncertain.
Overall Serious Adverse Events | 1 RCT (220)^17^ | “An adverse event that results in death, is life threatening, requires inpatient hospitalization or extends a current hospital stay, results in an ongoing or significant incapacity or interferes substantially with normal life functions, or causes a congenital anomaly or birth defect. Medical events that do not result in death, are not life threatening, or do not require hospitalization may be considered serious adverse events if they put the participant in danger or require medical or surgical intervention to prevent one of the results listed above.” | Fibrin: 22/164 (13.4); Saline: 7/56 (12.5); RR = 1.07 (0.5, 2.4); p = 1.0 | ⨁⨁◯◯^a,b^ Low; There may be little to no difference in adverse events with fibrin injections compared with saline injections.
Overall Adverse Events | 1 RCT (220)^17^ | Other adverse events, not including serious | Fibrin: 49/164 (29.9); Saline: 11/56 (19.6); RR = 1.05 (0.9, 2.7); p = 0.76 | ⨁⨁◯◯^a,b^ Low; There may be little to no difference in adverse events with fibrin injections compared with saline injections.

Notes.

a Downgraded for study limitations, study rated some concerns risk of bias;

b Downgraded for imprecision, wide confidence intervals;

c Downgraded for imprecision, optimal information size not met.

Abbreviations. NRS=Numeric Rating Scale; ODI=Oswestry Disability Index; RR=risk ratio; VAS=Visual Analog Scale.

### Discseel Intra-Annular Fibrin Injection System

We identified 1 uncontrolled, single site case series (N = 827; Pauza, 2024) evaluating the effectiveness of Discseel proprietary fibrin intervertebral injection products, system, and processes for low back pain compared with baseline at up to 3 years after treatment.^13^ The sample included adults with chronic low back pain (>6 months) who had failed physical therapy and prior invasive treatments including surgery, epidural corticosteroids or stem cell and platelet-rich plasma, intra-discal or interarticular zygophyseal joint injections or their combinations, radiofrequency neurotomy, or medical branch blocks. The exact number of failed prior procedures is unclear, as the abstract notes that “all patients underwent physical therapy and at least 4 invasive treatments without relief,” while the manuscript text notes patients had “experienced the failure of prior treatments such as…” without providing a number. Authors note that an MRI was obtained to rule out carcinoma, acute fracture, severe vertebral or intra-vertebral stenosis, or destabilizing spondylothisthesis.

Among individuals considered eligible (number not provided), those who agreed to the procedure then underwent Annulargrams, (also spelled annulograms), a procedure developed by the lead author and founder/president of the Discseel procedure company.^6^ This procedure used radiopaque contrast material to image each lumbar and sacral disc in the region of symptomatology (typically 4 discs), intending to detect early annulus fissures not detected on MRI images. If there was radiographic evidence of annular contrast leakage, then a solution containing a mixture of an unspecified amount and ratio of fibrin precursors was prepared and injected at an unspecified rate into the annulus (annular rings 22-25) via a trocar needle (Baxter Pharmaceuticals, LLC) (mean of 3.7 discs treated with 2.2 mL allogenic fibrin injected into each disc). Outcomes reported included pain intensity via the VAS, pain interference via the Oswestry Disability Index (ODI), quality of life via the EuroQoL, and serious adverse events (not defined).

The mean age of subjects was 54.8 years, 70% (580/827) were male, and 19% had prior back surgery (160/827). Among individuals with data reported (N = 667; 80.6% of the cohort), the mean BMI was 27.8 m^2^ while 95% (637/674) were not currently using tobacco.

Self-reported outcome measures are provided only for individuals who completed survey outcome measures at each follow-up time point. Fewer than 50% of all individuals completed study-related survey instruments at any follow-up time period. For example, only 698 (84.4%) individuals undergoing the procedure completed a baseline study survey. At 1 month post-procedure, 53.8% of those who completed the baseline measures (44.9% of all individuals; N = 371) provided information. At 1 year, only 35.2% of the entire cohort (N = 291; 41.7% of those who provided baseline information) provided information for pre-post comparison. Limiting the analyses to these individuals produces results subject to considerable responder bias.^19,20^ Though analyses were limited to study participants that responded at the specified follow-up time point, authors noted an improvement in VAS, ODI, and EuroQoL at all time points through 36 months, with approximately 50% of responding individuals (42% of the entire cohort) achieving a minimum clinically important difference in pain relief and physical function at 12 months. Improvements from baseline were observed in responders who had undergone prior surgery and those who had not undergone surgery. Authors stated that “there were no serious adverse events recorded throughout the study,” though no other information, including definition of serious adverse events, was provided.

Table 3 Key Characteristics and Outcomes of Discseel Study

Study; Study Design | Population | Intervention Characteristics | Comparator | Outcomes Assessed; Mean (SD)
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | cLBP >6months with failure of physical therapy and ≥4 invasive prior treatments (including surgery, intra-discal injections, radiofrequency neurotomy, or medical branch blocks); Mean age (SD): 54.8 (14.1); Female: 30%; Previous back surgery: 19%; BMI <25: 29%; BMI 25-29: 43%; BMI 30-34: 19%; BMI ≥35: 9% | Discseel fibrin intervertebral injection | Pre-post comparison | Pain Intensity (VAS, back); Baseline: 5.8 (2.4); 6 month: 3.7 (2.7); MD = −2.1 (NR) (p= 0.000); 12 month: 3.6 (2.8); MD = −2.2 (NR) (p = 0.000); 24 month: 3.5 (2.9); MD = −2.3 (NR) (p = 0.000); 36 month: 3.4 (3.0); MD = −2.4 (NR) (p = 0.000)
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | | Discseel fibrin intervertebral injection | Pre-post comparison | Pain Intensity (VAS, leg); Baseline: 4.4 (2.9); 6 month: 3.0 (2.7); MD = −1.4 (NR) (p = 0.000); 12 month: 2.9 (2.9); MD = −1.5 (NR) (p = 0.000); 24 month: 2.6 (2.7); MD = −1.9 (NR) (p = 0.000); 36 month: 2.5 (2.7); MD = −2.0 (NR) (p = 0.000)
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | | Discseel fibrin intervertebral injection | Pre-post comparison | Pain (NRS); Stated as assessed in methods, but no results reported.
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | | Discseel fibrin intervertebral injection | Pre-post comparison | Pain Interference (ODI); Baseline: 36.8 (16.1); 6 month: 25.7 (17.8); MD = −11.0 (NR) (p = 0.000); 12 month: 24.2 (19.3); MD = −12.6 (NR) (p = 0.000); 24 month: 23.3 (19.3); MD = −13.5 (NR) (p = 0.000); 36 month: 21.8 (19.5); MD = −15.0 (NR) (p = 0.000)
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | | Discseel fibrin intervertebral injection | Pre-post comparison | Quality of Life (EuroQoL); Baseline: 0.63 (0.09); 6 month: 0.69 (0.11); MD = 0.06 (p = 0.000); 12 month: 0.70 (0.11); MD = 0.07 (p = 0.000); 24 month: 0.70 (0.12); MD = 0.07 (p = 0.000); 36 month: 0.71 (0.11); MD = 0.07 (p = 0.000)
Pauza, 2024 ^13^; Uncontrolled single site case series; N = 827 | | Discseel fibrin intervertebral injection | Pre-post comparison | Adverse Events; “There were no serious adverse events recorded throughout the study.”

Abbreviations. cLBP=chronic low back pain; MD=mean difference; NR=not reported; NRS=Numeric Rating Scale; ODI=Oswestry Disability Index; SD=standard deviation; VAS=Visual Analog Scale.

Table 4 Summary of Available Evidence for Discseel

Outcome | Studies (Participants); Intervention | Measure | Summary of Findings | Certainty of Evidence
Pain Intensity | 1 uncontrolled observational^13^ (827) | VAS; (back and leg pain) | Pre-post comparisons among survey responders; statistically significant mean differences compared with baseline at 6, 12, 24 and 36 months among individuals who completed both baseline and follow-up surveys (less than 50% of all individuals at all follow-up time points) (Table 1) | ⨁◯◯◯^a^ Insufficient; The effect of fibrin injections on back pain is very uncertain.
Pain Interference | 1 uncontrolled observational^13^ (827) | ODI | Pre-post comparisons among survey responders; statistically significant mean differences compared with baseline at 6, 12, 24 and 36 months among individuals who completed both baseline and follow-up surveys (less than 50% of all individuals at all follow-up time points) (Table 1) | ⨁◯◯◯^a^ Insufficient; The effect of fibrin injections on pain interference is very uncertain.
Quality of Life | 1 uncontrolled observational^13^ (827) | EuroQol | Pre-post comparisons; statistically significant mean differences compared with baseline at 6, 12, 24 and 36 months among individuals who completed both baseline and follow-up surveys (less than 50% of all individuals at all follow-up time points) (Table 1) | ⨁◯◯◯^a^ Insufficient; The effect of fibrin injections on quality of life is very uncertain.
Adverse Events | 1 uncontrolled observational^13^ (827) | Undefined | “There were no serious adverse events recorded throughout the study.” | ⨁◯◯◯^a^ Insufficient; The effect of fibrin injections on adverse events is very uncertain.

Notes.

a Downgraded for study limitations: pre-post observational data.

Abbreviations. NRS=Numeric Rating Scale; ODI=Oswestry Disability Index; VAS=Visual Analog Scale.