# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD420251105334 (https://www.crd.york.ac.uk/PROSPERO/view/CRD420251105334)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1 (KQ1): Among adults with back or neck pain, what is the efficacy and safety of fibrin intervertebral injections?
  ○ Key Question 1a (KQ1a): Does efficacy and safety of fibrin intervertebral injections vary based on patient and condition characteristics?

Study eligibility criteria are shown in the table below.

Domain | Eligibility Criteria
Population | Adults with back or neck pain (with or without radiculopathy)
Intervention | Fibrin intervertebral injection (eg, Discseel)
Comparator | KQ1: Any; KQ1a: Different patient or condition characteristics (eg, comorbidities, treatment history [eg, epidural steroids; neck/back surgery], symptom severity/duration, degree of neurological/functional impairment [gait/walking distance], pain, vertebral location, presence of radiculopathy)
Outcomes | Pain intensity; Pain interference; Physical function (eg, physical performance measures); Quality of life; Post procedure pain medication use (analgesics, non-steroidals, opioids, gabapentin); Recurrent procedures or subsequent surgery; Complications or adverse events
Study Design | For pain intensity, pain interference, physical function outcomes, quality of life: RCTs, comparative cohort^a^; For subsequent medication use, recurrent procedures, subsequent surgery, complications or adverse events: RCTs, comparative cohort, case report, case series

Notes.

a If no comparative studies are identified, we will evaluate uncontrolled studies.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched MEDLINE (Ovid), CDSR and CENTRAL via Cochrane Library (Wiley), and Scopus (Elsevier) through June, 26 2025, using terms for back pain, neck pain, Discseel, Discseal, fibrin, annulargram, intra-annular or intra-discal (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included study was rated using modified versions of the Joanna Briggs Institute cohort and case series Critical Appraisal Checklists (see Appendix for risk of bias ratings).^15^ All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus.

## SYNTHESIS

Due to lack of data, quantitative synthesis was not possible. We narratively summarized the results.

### Certainty of Evidence

After synthesizing available evidence, we rated the certainty of evidence for each outcome based on the methodology and risks of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers) with the Grading of Recommendations, Assessment, Development and Evaluation (GRADE) approach.^16^ Outcomes were rated as high (we are very confident that the true effect lies close to that of the estimate of the effect), moderate (we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different), low (our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect) or very low (we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect).