# BACKGROUND

Neck and back pain are important health care issues in the United States, leading to more disability than any other medical condition.^1–3^ Common causes of neck and back pain include damaged or degenerated spinal discs.^4^ Spinal discs are comprised of an external fibrocartilaginous ring, annulus fibrosis, an internal gel-like central nucleus pulposus, and a cartilaginous endplate that anchors discs to adjacent vertebrate. Discs cushion and serve as the principal joint between vertebrae within the spinal column. However, damage to the disc can stem from daily activities, aging, or injuries. Damage includes tears in the annulus fibrosis and protrusion or herniation of the nucleus pulposus. Discogenic back pain is a term used to describe primarily axial/central back pain believed to be emanating from the disc itself secondary to disc degeneration, without disc herniation or other obvious causes of pain. Discogenic back pain is inferred from clinical examination and radiographic imaging including magnetic resonance imaging (MRI) scans.

While most spinal disc tears or protrusions are asymptomatic, they can result in severe acute and chronic pain and disability.^5^ A potential result of annular tears is extrusion of the internal disc gel-like fluid. This leakage may cause pain and other symptoms.^6^ Among individuals with symptoms, most have resolution within days to weeks without additional therapy or with physical therapy, over-the-counter pain medications, or cognitive behavioral therapy.^7,8^ Among individuals not adequately responding to initial approaches, epidural steroid injections are often utilized.^9^ For patients with inadequate response to non-surgical management, surgical procedures with or without fusion of adjacent vertebrae may be undertaken including partial or total disc removal, laminectomy, or disc replacement. However, their long-term effectiveness is limited, they can result in harms, and some individuals are not acceptable surgical candidates or are reluctant to undergo surgery.^10–12^

There is growing interest in less invasive treatments for discogenic pain. These include “regenerative treatments” with spinal injections into the annulus fibrosis or nucleus pulposus of anti-inflammatory preparations, tissue growth factors, neurotropic agents, cell and extracellular additives, and tissue scaffolds; information on their efficacy and harms is limited. One option, the Discseel procedure, uses a fibrin biologic (a bio-adhesive) injected under fluoroscopic imaging into the annulus fibrosis of each disc in the region of pain to seal tears identified on Annulargram.^6,13^ Another option injects a proprietary BIOSTAT BIOLOGX Fibrin Sealant with the Biostat Delivery Device into the nucleus pulposus following provocative discograms.^14^ In each case, the injected fibrin reportedly binds to and seals the damaged annular fibrosis (or disc) and facilitates new disc tissue growth. Once injected, fibrin is stated to serve as a sealant and enhance the repair process by acting as a biological glue, providing a scaffold for fibroblast growth, and stimulating reparative cells to “seal, heal, and promote” healthy new disc tissue and improve pain and function.^6,13,14^ While fibrin is approved by the Food and Drug Administration (FDA) as a natural biologic to treat bleeding in limited situations, its specific use for repairing and sealing tears in compromised discs to improve pain and function is considered an off-label use. Neither fibrin nor the Discseel procedure or Biostat Delivery Device have current FDA approval for treatment of neck or back conditions.

In response to a request from the Veterans Health Administration (VHA) Office of Integrated Veteran Care Clinical Determinations Unit (CDU) and the Pain Management Opioid Safety and Prescription Drug Monitoring Program (PMOP), we conducted a systematic review on the efficacy and safety of fibrin intervertebral injections (eg, Discseel). This review will be used to inform development of a Clinical Determination and Indication (CDI) document to help community clinicians and VHA staff determine if a Veteran meets the clinical criteria for this, or similar, procedures.