# Appendices

## SEARCH STRATEGIES

### MEDLINE (OVID) AND EPUB AHEAD OF PRINT AND IN-PROCESS, IN-DATA-REVIEW & OTHER NON-INDEXED CITATIONS (DAILY 1946 TO JUNE 25, 2025)

# | Search Statement | Results
1 | (annulargram* or discseel* or discseal* or (disc adj3 sealant*) or ((intra-annular or intraannular or intra-discal or intradiscal) adj1 (biologic treatment* or fibrin))).ti,ab,kf. | 9
2 | (fibrin sealant* or tisseel).ti,ab,kf. adj3 (exp Back/ or exp Intervertebral Disc/ or exp Neck/ or Radiculopathy/ or Sciatica/ or exp Spine/ or (back* or cervical or disc* or lumbar or neck* or radiculopath* or sciatica or spine* or spinal).ti,ab,kf.) | 215
3 | 1 or 2 | 220
| Total | 220

Search date: 06/26/2015

### CENTRAL (WILEY)

# | Search Statement | Results
1 | (annulargram* or discseel* or discseal* or (disc NEAR/3 sealant*) or ((intra-annular or intraannular or intra-discal or intradiscal) NEAR/1 (biologic treatment* or fibrin))):ti,ab,kw | 7
2 | (fibrin sealant* or tisseel):ti,ab,kw | 579
3 | MeSH descriptor: [Back] explode all trees | 998
4 | MeSH descriptor: [Intervertebral Disc] explode all trees | 373
5 | MeSH descriptor: [Neck] explode all trees | 783
6 | MeSH descriptor: [Radiculopathy] this term only | 0
7 | MeSH descriptor: [Sciatica] this term only | 420
8 | MeSH descriptor: [Spine] explode all trees | 0
9 | (back* or cervical or disc* or lumbar or neck* or radiculopath* or sciatica or spine* or spinal):ti,ab,kw | 721856
10 | {or #3-#9} | 721925
11 | #2 and #10 | 234
12 | #1 or #11 | 240
| Total | 240

Search date: 06/26/2025

### SCOPUS (ELSEVIER)

# | Search Statement | Results
1 | TITLE-ABS-KEY(annulargram* or discseel* or discseal* or (disc W/3 sealant*) or ((intra-annular or intraannular or intra-discal or intradiscal) W/1 ((biologic W/1 treatment*) or fibrin))) | 28
2 | (TITLE-ABS-KEY((fibrin W/1 sealant*) or tisseel)) W/3 (TITLE-ABS-KEY(back* or cervical or disc* or lumbar or neck* or radiculopath* or sciatica or spine* or spinal)) | 251
3 | 1 or 2 | 269
| Total | 269

Search date: 06/26/2025

Overall Results
| Total results across databases | 729
| Total after deduplication | 555

## DETAILED RISK OF BIAS RATINGS

### RISK OF BIAS RATINGS FOR UNCONTROLLED STUDIES

Critical Appraisal Question^a^ | Pauza, 2024^13^ | Yin, 2014^14^
Were there clear criteria for inclusion in the case series? | No.; Unclear, abstract and text differ in number of prior failed therapies (though patients had chronic low back pain of ≥6 m), no description of what MRI/X-ray, clinical criteria needed, no information about those potentially eligible for procedure but with Annulargram that did not have a “leak” | Yes.; Chronic single level axial/discogenic low back pain ≥6mo with failure of prior nonsurgical treatments.
Was the condition measured in a standard, reliable way for all participants included in the case series? | No.; Unclear, no description of how condition diagnosed | Yes.; “The diagnosis of symptomatic IDD was made with pressure- and volume-controlled provocation discography performed in rigorous compliance with published standards.”
Were valid methods used for identification of the condition for all participants included in the case series? | No.; “Annulargram” methods are proprietary, developed by author, have not been validated, are not widely used, and it is not clear how many patients with different or lack of symptoms have “Annulargram” findings | Yes.; “The diagnosis of symptomatic IDD was made with pressure- and volume-controlled provocation discography performed in rigorous compliance with published standards.”
Did the case series have complete inclusion of participants? | Unclear.; No information provided about those that did not meet inclusion criteria, including those with negative Annulargrams. | Unclear.; No information provided about those that did not meet inclusion criteria.
Were the groups/participants free of the outcome at the start of the study (or at the moment of exposure)? | Yes.; Chronic low back pain ≥6 mo with failure of prior treatments. | Yes.; Chronic single level axial/discogenic low back pain ≥6 mo with failure of prior nonsurgical treatments.
Were confounding factors identified? | Unclear.; Does not provide information about concomitant interventions. | Unclear.; Does not provide information about concomitant interventions.
Were the outcomes measured in a valid and reliable way? | No.; Validated measures for pain and quality of life used. However, patients and outcome assessors were aware of treatment received which can influence the reliability patient-reported outcomes. | No; Validated measures for pain used.; However, patients and outcome assessors were aware of treatment received which can influence the reliability patient reported outcomes
Was the follow-up time reported and sufficient to be long enough for outcomes to occur? | Yes.; 36 months | Yes.; 104 weeks
Was appropriate statistical analysis used? | Yes.; However, pre-post comparisons made, patients and interventionalists were not blinded to intervention. | Yes.; However, pre-post comparisons made, patients and interventionalists were not blinded to intervention.
Was there clear reporting of the demographics of the participants in the study? | Yes.; Age, sex, BMI. | Yes.; Age, sex.
Was there clear reporting of clinical information of the participants? | Yes.; Alcohol and tobacco use, previous back surgery. However, no information about lumbar levels or number of “leaks.” | Yes.; Number treated discs and levels treated
Were the outcomes or follow-up results of cases clearly reported? | Yes. | Yes.

a Selected questions from the Johanna Briggs Institute Critical Appraisal tools for cohorts and case series.

### RISK OF BIAS RATINGS FOR RANDOMIZED CONTROLLED TRIALS

Trial Name or Author Year | Bias from Randomization Process | Bias from Deviation from Intended Interventions (Assignment) | Bias from Deviation from Intended Interventions (Adherence) | Bias from Missing Outcome Data | Bias in Measurement of Outcome | Bias in Selection of Reported Result | Overall Risk of Bias
Pauza, 2014; NCT01011816 (https://clinicaltrials.gov/study/NCT01011816?term=nct01011816&rank=1) | Some concerns | Low | High | Low | Some concerns | Low | High

## EXCLUDED STUDIES

1 Elder BD, Witham TF. Fibrin Sealants, Platelet Gels, and Spinal Fusion. World Neurosurg. 2016;95:613. Ineligible publication type27923470
2 Kallewaard JW, Geurts JW, Kessels A, Willems P, van Santbrink H, van Kleef M. Efficacy, Safety, and Predictors of Intradiscal Methylene Blue Injection for Discogenic Low Back Pain: Results of a Multicenter Prospective Clinical Series. Pain Pract. 2016;16(4):405–12. Ineligible intervention25753429
3 Pauza KJ, Moradian M, Lutz G. Intra-annular Fibrin Discseel®. Regenerative Medicine: Springer International Publishing; 2023:61–71. No eligible outcomes provided
4 Pauza K. Intradiscal Biologic Treatments: Intra-annular Fibrin Disc Sealant. Advanced Procedures for Pain Management: Springer International Publishing; 2018:525–36. No eligible outcomes provided
5 Pauza K, Wright C, Fairbourn A. Treatment of annular disc tears and “leaky disc syndrome” with fibrin sealant. Techniques in Regional Anesthesia and Pain Management. 2015;19(1–2):45–9. No eligible outcomes provided
6 Petersohn JD. Discogenic Pain. Diagnosis, Management, and Treatment of Discogenic Pain: Elsevier; 2012:75–9. No eligible outcomes provided
7 Yu J, Taylor W, Verrills P, . Results of a Pilot Study on the Safety and Early Efficacy of Novel Polymethyl Methacrylate Microspheres and a Hyaluronic Acid Device for the Treatment of Low Back Pain Caused by Degenerative and Diseased Intervertebral Discs of the Lumbar Spine. Cureus. 2021;13(7):e16308. Ineligible intervention34405067

## PEER REVIEW COMMENTS AND RESPONSES

Are the objectives, scope, and methods for this review clearly described?
Comment # | Reviewer # | Comment | Author Response
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 5 | Yes | Thank you.
5 | 6 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
Comment # | Reviewer # | Comment | Author Response
6 | 1 | No | Thank you.
7 | 2 | No | Thank you.
8 | 4 | No | Thank you.
9 | 5 | No | Thank you.
10 | 6 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
Comment # | Reviewer # | Comment | Author Response
11 | 1 | No | Thank you.
12 | 2 | No | Thank you.
13 | 4 | No | Thank you.
14 | 5 | No | Thank you.
15 | 6 | No | Thank you.
Additional suggestions or comments?
Comment # | Reviewer # | Comment | Author Response
16 | 1 | The authors are commended for an excellent systematic review.; Given the very low quality of the evidence reported for Discseel, with multiple identified risks of bias including the noted misrepresentation of a major financial conflict of interest on publication (Pauza 2024), the conclusion that RCTs of Discseel are needed prior to “widespread implementation” is understated.; Suggest rephrasing the conclusion language to align better with the paucity of evidence that was found. Something along the lines of: “use cannot be recommended based on the current state of the evidence.”; Also suggest caution about the language used related to future research. Given limited resources for studying pain interventions, a recommendation to conduct future large multicenter RCTs should be reserved for interventions with more promising initial data. | Thank you; We appreciate this comment. However, our evidence reports avoid including “recommendation statements”. These are better reserved for clinical policy and guideline committees for which our evidence report provides data that can be used to develop those recommendations. We have rephrased the final conclusion sentence to read: Prior to widespread implementation, evidence of effectiveness from randomized controlled trials of fibrin injection for back and neck pain are needed. Especially evaluating the Discseel Intra-Annular Fibrin Injection System.; We agree that especially for the Biostat Biologx intradisc system that future large multicenter RCTs are unlikely to be indicated. Given the uncertainty for Discseel Intra-Annular Fibrin Injection System and its use, a large well-designed RCT would be ethical and potentially needed. Resources to conduct such a trial could be based on “industry funding” as is done with many “emerging technologies.” Regardless, we provide suggestions for future research in the full report. Furthermore, future technologies that generally employ fibrin injections may be of interest, especially given the large burden of neck and low back pain as well as the postulated role of fibrin injection as a potential therapeutic option. We believe the revision to our conclusion along with current research limitations and future research needs strikes that balance.
17 | 2 | None | Thank you.
18 | 4 | None | Thank you.
19 | 5 | This is a well written and substantiated report.; My only comment for revision is to clarify lines 35-38 in page 9. It says that “…who received fibrin injection had significantly greater reduction…compared with Biostat Biologx…”. I think one of the groups in that line is likely referring to Saline (not Fibrin). | Thank you, you are correct, the line should have read “…compared with saline.” We have fixed this.
20 | 6 | The review is an excellent summary of the findings associated with initradiscal injection. This is not a critique but there are animal models that have demonstrated a proof of concept that may be helpful as a prelude to the human studies mentioned so that the reader is aware modeling was first done in animals. Having said that, I think this is a very useful summary of the findings for clinicians. | Thank you. Including information on animal models is outside the scope of this report. We provide information in the introduction regarding biologic plausibility for fibrin injections and other “regenerative treatments” for back pain as well as FDA approval for use of fibrin for other medical indications.