# ABBREVIATIONS TABLE

Abbreviation: Definition
ARD: Absolute risk difference
CDI: Clinical determination and indication
CDU: Care Clinical Determinations Unit
COE: Certainty of evidence
FDA: Food and Drug Administration
KQ: Key question
MRI: Magnetic resonance imaging
ODI: Oswestry Disability Index
PMOP: Pain Management Opioid Safety and Prescription Drug Monitoring Program
RCT: Randomized controlled trial
RMDQ: Roland-Morris Disability Questionnaire
RR: Risk ratio
VAS: Visual analog scale
VHA: Veterans Health Administration