# REFERENCES

1 Bray F, Ferlay J, Soerjomataram I, Siegel RL, Torre LA, Jemal A. Global cancer statistics 2018: GLOBOCAN estimates of incidence and mortality worldwide for 36 cancers in 185 countries. CA Cancer J Clin. 2018;68(6):394–424.30207593
2 Seto Y, Mori K, Aikou S. Robotic surgery for esophageal cancer: Merits and demerits. Ann Gastroenterol Surg. 2017;1(3):193–198.29863149
3 Wang W, Liu F, Hu T, Wang C. Matched-pair comparisons of minimally invasive esophagectomy versus open esophagectomy for resectable esophageal cancer: A systematic review and meta-analysis protocol. Medicine (Baltimore). 2018;97(28):e11447.29995799
4 Little AG, Lerut AE, Harpole DH, . The Society of Thoracic Surgeons practice guidelines on the role of multimodality treatment for cancer of the esophagus and gastroesophageal junction. Ann Thorac Surg. 2014;98(5):1880–1885.25262396
5 Yibulayin W, Abulizi S, Lv H, Sun W. Minimally invasive oesophagectomy versus open esophagectomy for resectable esophageal cancer: a meta-analysis. World J Surg Oncol. 2016;14(1):304.27927246
6 Mariette C, Markar SR, Dabakuyo-Yonli TS, . Hybrid Minimally Invasive Esophagectomy for Esophageal Cancer. N Engl J Med. 2019;380(2):152–162.30625052
7 Biere SS, van Berge Henegouwen MI, Maas KW, . Minimally invasive versus open oesophagectomy for patients with oesophageal cancer: a multicentre, open-label, randomised controlled trial. Lancet. 2012;379(9829):1887–1892.22552194
8 Straatman J, van der Wielen N, Cuesta MA, . Minimally Invasive Versus Open Esophageal Resection: Three-year Follow-up of the Previously Reported Randomized Controlled Trial: the TIME Trial. Ann Surg. 2017;266(2):232–236.28187044
9 Melvin WS, Needleman BJ, Krause KR, . Computer-enhanced robotic telesurgery. Initial experience in foregut surgery. Surg Endosc. 2002;16(12):1790–1792.12239646
10 Qureshi YA, Dawas KI, Mughal M, Mohammadi B. Minimally invasive and robotic esophagectomy: Evolution and evidence. J Surg Oncol. 2016;114(6):731–735.27539093
11 Higgins JP AD, Gøtzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ. 2011:343:d5928.22008217
12 Sterne JA HM, Reeves BC, . . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016:355:i4919.27733354
13 GRADE working group. http://www.gradeworkinggroup.org/. Published 2014. Accessed 04/26/2019.
14 van der Sluis PC, van der Horst S, May AM, . Robot-assisted Minimally Invasive Thoracolaparoscopic Esophagectomy Versus Open Transthoracic Esophagectomy for Resectable Esophageal Cancer: A Randomized Controlled Trial. Ann Surg. 2019;269(4):621–630.30308612
15 He ZF, Zheng TL, Liu DL, . [Comparison of short-term and long-term efficacy between robot-assisted and thoracoscopy-laparoscopy-assisted radical esophageal cancer surgery]. Zhonghua Wei Chang Wai Ke Za Zhi. 2020;23(4):390–395.32306608
16 Chao YK, Hsieh MJ, Liu YH, Liu HP. Lymph Node Evaluation in Robot-Assisted Versus Video-Assisted Thoracoscopic Esophagectomy for Esophageal Squamous Cell Carcinoma: A Propensity-Matched Analysis. World J Surg. 2018;42(2):590–598.28801820
17 Chen J, Liu Q, Zhang X, . Comparisons of short-term outcomes between robot-assisted and thoraco-laparoscopic esophagectomy with extended two-field lymph node dissection for resectable thoracic esophageal squamous cell carcinoma. J Thorac Dis. 2019;11(9):3874–3880.31656660
18 Deng HY, Luo J, Li SX, . Does robot-assisted minimally invasive esophagectomy really have the advantage of lymphadenectomy over video-assisted minimally invasive esophagectomy in treating esophageal squamous cell carcinoma? A propensity score-matched analysis based on short-term outcomes. Dis Esophagus. 2019;32(7).
19 Espinoza-Mercado F, Imai TA, Borgella JD, . Does the Approach Matter? Comparing Survival in Robotic, Minimally Invasive, and Open Esophagectomies. Ann Thorac Surg. 2019;107(2):378–385.30312615
20 He H, Wu Q, Wang Z, . Short-term outcomes of robot-assisted minimally invasive esophagectomy for esophageal cancer: a propensity score matched analysis. J Cardiothorac Surg. 2018;13(1):52.29792203
21 Jeong DM, Kim JA, Ahn HJ, Yang M, Heo BY, Lee SH. Decreased Incidence of Postoperative Delirium in Robot-assisted Thoracoscopic Esophagectomy Compared With Open Transthoracic Esophagectomy. Surg Laparosc Endosc Percutan Tech. 2016;26(6):516–522.27846169
22 Naffouje SA, Salloum RH, Khalaf Z, Salti GI. Outcomes of Open Versus Minimally Invasive Ivor-Lewis Esophagectomy for Cancer: A Propensity-Score Matched Analysis of NSQIP Database. Ann Surg Oncol. 2019;26(7):2001–2010.30927192
23 Tagkalos E, Goense L, Hoppe-Lotichius M, . Robot-assisted minimally invasive esophagectomy (RAMIE) compared to conventional minimally invasive esophagectomy (MIE) for esophageal cancer: a propensity-matched analysis. Dis Esophagus. 2019.
24 Yang Y, Zhang X, Li B, . Short- and mid-term outcomes of robotic versus thoraco-laparoscopic McKeown esophagectomy for squamous cell esophageal cancer: a propensity score-matched study. Dis Esophagus. 2019.
25 Yun JK, Chong BK, Kim HJ, . Comparative outcomes of robot-assisted minimally invasive versus open esophagectomy in patients with esophageal squamous cell carcinoma: a propensity score-weighted analysis. Dis Esophagus. 2019.
26 Zhang Y, Han Y, Gan Q, . Early Outcomes of Robot-Assisted Versus Thoracoscopic-Assisted Ivor Lewis Esophagectomy for Esophageal Cancer: A Propensity Score-Matched Study. Ann Surg Oncol. 2019;26(5):1284–1291.30843161
27 Meredith KL, Maramara T, Blinn P, Lee D, Huston J, Shridhar R. Comparative Perioperative Outcomes by Esophagectomy Surgical Technique. J Gastrointest Surg. 2019.
28 Sarkaria IS, Rizk NP, Goldman DA, . Early Quality of Life Outcomes After Robotic-Assisted Minimally Invasive and Open Esophagectomy. Ann Thorac Surg. 2019;108(3):920–928.31026433
29 Washington K, Watkins JR, Jay J, Jeyarajah DR. Oncologic Resection in Laparoscopic Versus Robotic Transhiatal Esophagectomy. Jsls. 2019;23(2).
30 Motoyama S, Sato Y, Wakita A, . Extensive Lymph Node Dissection Around the Left Laryngeal Nerve Achieved With Robot-assisted Thoracoscopic Esophagectomy. Anticancer Res. 2019;39(3):1337–1342.30842166
31 Park S, Hwang Y, Lee HJ, Park IK, Kim YT, Kang CH. Comparison of robot-assisted esophagectomy and thoracoscopic esophagectomy in esophageal squamous cell carcinoma. J Thorac Dis. 2016;8(10):2853–2861.27867561
32 Osaka Y, Tachibana S, Ota Y, . Usefulness of robot-assisted thoracoscopic esophagectomy. Gen Thorac Cardiovasc Surg. 2018;66(4):225–231.29397486
33 HC. R, RB. A, M. B, . Robot-assisted hybrid esophagectomy is associated with a shorter length of stay compared to conventional transthoracic esophagectomy, a retrospective study. http://wwwwhoint/trialsearch/Trial2aspx?TrialID=DRKS00013023. 2017.
34 Gong L, Jiang H, Yue J, . Comparison of the short-term outcomes of robot-assisted minimally invasive, video-assisted minimally invasive, and open esophagectomy. J Thorac Dis. 2020;12(3):916–924.32274159
35 Van Der Sluis PC, Van Der Horst S, May AM, . Robot-assisted minimally invasive thoracolaparoscopic esophagectomy versus open transthoracic esophagectomy for resectable esophageal cancer: A randomized controlled trial. Journal of Clinical Oncology. 2018;36(4).
36 Na KJ, Park S, Park IK, Kim YT, Kang CH. Outcomes after total robotic esophagectomy for esophageal cancer: a propensity-matched comparison with hybrid robotic esophagectomy. J Thorac Dis. 2019;11(12):5310–5320.32030248
37 Collaborators GBDOC. The global, regional, and national burden of oesophageal cancer and its attributable risk factors in 195 countries and territories, 1990-2017: a systematic analysis for the Global Burden of Disease Study 2017. Lancet Gastroenterol Hepatol. 2020;5(6):582–597.32246941
38 Napier KJ, Scheerer M, Misra S. Esophageal cancer: A Review of epidemiology, pathogenesis, staging workup and treatment modalities. World J Gastrointest Oncol. 2014;6(5):112–120.24834141
39 Then EO, Michell Lopez SS, Gayam V, Sunkara T, Culliford A, Gaduputi V. Esophageal Cancer: An Updated Surveillance Epidemiology and End Results Database Analysis. World Journal of Oncology. 2020;11(2):55.32284773
40 Grochola LF, Soll C, Zehnder A, Wyss R, Herzog P, Breitenstein S. Robot-assisted versus laparoscopic single-incision cholecystectomy: results of a randomized controlled trial. Surg Endosc. 2019;33(5):1482–1490.30218263
41 Alleblas CCJ, de Man AM, van den Haak L, Vierhout ME, Jansen FW, Nieboer TE. Prevalence of Musculoskeletal Disorders Among Surgeons Performing Minimally Invasive Surgery: A Systematic Review. Ann Surg. 2017;266(6):905–920.28306646
42 Stucky CH, Cromwell KD, Voss RK, . Surgeon symptoms, strain, and selections: Systematic review and meta-analysis of surgical ergonomics. Ann Med Surg (Lond). 2018;27:1–8.29511535
43 Yang L, Wang T, Weidner TK, Madura JA, 2nd, Morrow MM, Hallbeck MS. Intraoperative musculoskeletal discomfort and risk for surgeons during open and laparoscopic surgery. Surg Endosc. 2020.
44 van der Sluis PC, Ruurda JP, van der Horst S, Goense L, van Hillegersberg R. Learning Curve for Robot-Assisted Minimally Invasive Thoracoscopic Esophagectomy: Results From 312 Cases. Ann Thorac Surg. 2018;106(1):264–271.29454718
45 Kamarajah SK, Navidi M, Wahed S, . Anastomotic Leak Does Not Impact on Long-Term Outcomes in Esophageal Cancer Patients. Ann Surg Oncol. 2020;27(7):2414–2424.31974709
46 Ramirez PT, Frumovitz M, Pareja R, . Minimally Invasive versus Abdominal Radical Hysterectomy for Cervical Cancer. N Engl J Med. 2018;379(20):1895–1904.30380365
47 Abbas H, Rossidis G, Hochwald SN, Ben-David K. Robotic esophagectomy: new era of surgery. Minerva Chir. 2013;68(5):427–433.24101000
48 Rao Z, Zhou H, Pan X, . Ropivacaine wound infiltration: a fast-track approach in patients undergoing thoracotomy surgery. J Surg Res. 2017;220:379–384.29180206
49 Fukuda N, Shichinohe T, Ebihara Y, . Thoracoscopic Esophagectomy in the Prone Position Versus the Lateral Position (Hand-assisted Thoracoscopic Surgery): A Retrospective Cohort Study of 127 Consecutive Esophageal Cancer Patients. Surg Laparosc Endosc Percutan Tech. 2017;27(3):179–182.28399060