# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Mark Wilson, MD, PhD and William Gunnar, MD, JD, FACHE for the purpose of understanding the potential benefits and costs for robot-assisted surgery. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Sachi Yagyu and Zhaoping Li for their contributions to this project.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Mark Wilson, MD, PhD
  National Director of Surgery
  Department of Veterans Affairs
- William Gunnar, MD, JD, FACHE
  Director, National Center for Patient Safety
  VA Ann Arbor Healthcare System
  Associate Professor of Surgery, University of Michigan Medical School

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Rajeev Dhupar, MD, MBA, FACS
  Assistant Professor of Cardiothoracic Surgery
  Chief, Thoracic Surgery
  VAMC of Pittsburgh Department of Cardiothoracic Surgery
- Nir N. Hoftman, MD
  Clinical Professor, Anesthesiologist
  Director, Thoracic Anesthesia
  UCLA Department of Anesthesiology
- James D. Maloney, MD
  Chief of Surgical Services at William S. Middleton Memorial Veterans Hospital
  Chief, Section of Thoracic Surgery
  University of Wisconsin Health System
- Daniel C. Wiener, MD
  Chief, Thoracic Surgery, VA Boston Healthcare System, West Roxbury
  Assistant Professor of Surgery, Thoracic Surgery
  Harvard Medical School

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.