# RESULTS

We identified 390 potentially relevant citations, of which 146 were included at the abstract screening level. From these, a total of 101 abstracts were excluded: Wrong comparison (n=66), wrong intervention (n=1), review/editorial (n=19), systematic review (n=7), and protocol (n=8). This left 45 publications for full-text review, of which 23 publications were excluded for the following reasons: wrong intervention (n=6), wrong comparison (n=3), small sample size (n=1), not original research (n=1), duplicate or studies with a large overlap of patients from the same data source (n=11), and unavailable (n=1). A full list of excluded studies from the full-text review is included in Appendix I. A total of 22 publications were identified at full-text review as meeting initial inclusion criteria: 20 publications with clinical outcomes, 1 publication with both clinical and cost outcomes, and 1 publication with only cost outcomes. See Figure 1 for literature flow. Descriptions of included publications are available in the Evidence Table (Appendix G).

## DESCRIPTION OF EVIDENCE

We identified 22 publications that met the inclusion criteria, of which 1 only reported cost data. As such, 21 studies reported clinical outcomes. Of these, 2 were RCTs,^14,15^ and the remaining were observational studies. One RCT from the Netherlands randomized 109 patients with esophageal cancer to RAMIE (robot-assisted thoracic portion and laparotomy) or open esophagectomy (thoracotomy and laparotomy).^14^ The other RCT from China randomized 192 patients with esophageal squamous cell carcinoma to RAMIE (robot-assisted thoracic and abdominal portions) or total thoracolaparoscopic MIE.^15^ Both RCTs reported intra-operative, short-term, and long-term, cancer-specific outcomes.

Of the 19 observational studies, 11 were propensity matched for patient characteristics and pre-operative factors, such as age, sex, BMI, certain comorbidities, receipt of neoadjuvant treatment, and clinical cancer staging.^16–26^ The majority of the observational studies were from East Asia, with only 5 studies coming from the US.^19,22,27–29^ The robot and non-robot cohorts of each study had comparable surgical approaches and varied in size from 36 to 5,553 patients. Ten observational studies compared transthoracic RAMIE with MIE.^16–18,20,22–24,26,30,31^ Four studies compared transthoracic RAMIE with open esophagectomy.^21,25,28,32^ One study utilized the robot for the abdominal portion only.^33^ Three studies compared MIE, RAMIE, and open esophagectomy,^19,27,34^ and 1 study compared transhiatal MIE with transhiatal RAMIE.^29^ Two studies were from large national databases.^19,22^ The study from the National Surgical Quality Improvement Program (NSQIP) database compared open esophagectomy with all minimally invasive esophagectomies (RAMIE and MIE combined) for the primary analysis but performed a secondary analysis comparing MIE and RAMIE with 2:1 propensity matching.^22^ Only data from the secondary analysis was abstracted for this review. The other database study analyzed patients from the National Cancer Database and compared RAMIE, MIE, and open esophagectomy.^19^

All observational studies reported intra-operative and short-term outcomes, but only one-third reported long-term, cancer-specific outcomes. The majority of studies described tumor location and histologic type of cancer. Due to epidemiologic differences in esophageal cancer subtype, patients in the studies from East Asia primarily had squamous cell carcinoma, and the patients in the US studies predominantly had adenocarcinoma. Certain pre-operative factors, such as tumor location, stage, receipt of neoadjuvant therapy, and location of the anastomosis are known to correlate with perioperative outcomes and are shown for each study in Appendix G. The surgical approach (eg, McKeown, Ivor-Lewis), operative technique for the thoracic and abdominal portions, and location and method of creating the anastomosis are provided in more detail in Appendix H (Operative Techniques of Included Studies).

For clarity, we elected to refer to robot-assisted study arms as robot-assisted minimally invasive esophagectomy (RAMIE) for the remainder of our report. Likewise, we refer to all video-assisted arms as video-assisted minimally invasive esophagectomy (VAMIE), which includes the different varieties and combinations of thoracoscopic/laparoscopic approaches.

Figure 1 Literature Flow Chart

## KEY QUESTION 1 What is the clinical effectiveness of robot-assisted esophagectomy compared to thoracoscopic/laparoscopic or open esophagectomy for cancer?

### Intra-operative Outcomes

#### Intra-operative: RAMIE compared with VAMIE

Figure 2 presents 3 intra-operative outcomes: OR time, LN harvest, and EBL. For the RCT,^15^ OR time was not longer for RAMIE as compared to VAMIE. The number of LNs harvested was greater for RAMIE, and EBL was not different. For the observational studies, OR time was reported as longer for RAMIE in 4 of the matched studies^18,20,23,26^ and as no difference in 3 of the other matched studies.^16,17,22^ One matched study reported shorter OR time^24^ for RAMIE. For the unmatched observational studies, 1 reported longer OR time with RAMIE^27^ and 4 reported no difference.^29–31,34^ Two of the matched studies reported a greater number of LNs harvested for RAMIE,^18,19^ whereas 6 reported no difference.^16,17,20,23,24,26^ For unmatched observational studies, 2 reported greater number of LNs harvested with RAMIE,^27,31^ and 3 reported no difference.^29,30,34^ None of the matched or unmatched observational studies reported differences in EBL for RAMIE as compared to VAMIE.^16–18,20,23,24,26,27,30,31,34^

#### Intra-operative: RAMIE compared with Open Esophagectomy

For the RCT,^14^ OR time was significantly longer for RAMIE compared to the open approach. The number of lymph nodes harvested was not different in the RAMIE arm. EBL was less for RAMIE. For the observational studies, there was a signal of longer OR time for RAMIE (4 reported significantly longer;^25,27,32,34^ 3 no difference^21,28,33^). Seven studies reported on the number of LNs harvested and of these, 3 reported higher numbers removed by the RAMIE approach.^19,27,32^ More than half of the observational studies reported less EBL with RAMIE^27,28,32,33^ whereas 3 reported no difference.^21,25,34^

Figure 2 Intra-operative Outcomes

^1^Dotted line separates RCT from the observational studies

^2^Solid line separates the studies comparing RAMIE with VAMIE or RAMIE with open esophagectomy

### Short-term Post-operative Outcomes

Figure 3 presents 6 short-term post-operative outcomes: anastomotic leak, recurrent laryngeal nerve palsy/hoarseness, pulmonary complications, duration of hospitalization, total complications, and mortality. Twelve studies compared RAMIE vs VAMIE,^15–18,20,22–24,26,29–31^ 6 studies compared RAMIE with open esophagectomy,^14,21,25,28,32,33^ and 3 studies compared RAMIE with both VAMIE and open esophagectomy.^19,27,34^

#### Short-Term: RAMIE compared with VAMIE

Of the studies comparing RAMIE with VAMIE, 14 assessed anastomotic leak, and there was no significant difference between study arms or trend favoring RAMIE or VAMIE in either the RCT or the 8 matched and 5 unmatched observational studies.^15–18,20,22–24,26,27,29–31,34^ Cervical anastomoses were used in 9 studies, including 8 studies primarily or exclusively utilizing the McKeown approach^15–18,20,24,31,34^ and 1 utilizing a transhiatal approach.^29^ Three studies directly compared intrathoracic anastomoses with an Ivor-Lewis approach in both study arms.^22,23,26^ One study was from a large database and compared robot-assisted Ivor-Lewis with an unspecified “transthoracic” MIE, suggesting at least 1 study arm had an intrathoracic anastomosis.^27^ Another study reported a transthoracic approach for both study arms but did not specify whether an intrathoracic or cervical anastomosis was performed.^30^ There was no clear difference favoring RAMIE or VAMIE when evaluating studies with a cervical or intrathoracic anastomosis separately.

The RCT found no difference in recurrent laryngeal nerve (RLN) palsy between study arms.^15^ Of the 6 matched observational studies assessing RLN injury, 1 reported lower RLN palsy with RAMIE,^17^ 1 reported lower RLN palsy with VAMIE,^24^ and 4 reported no difference.^16,19,20,26^ For the 3 unmatched studies, 1 reported lower rate of RLN palsy as compared to RAMIE,^30^ and 2 reported no difference.^31,34^

The RCT^15^ did not report a difference in pulmonary complications for RAMIE as compared to VAMIE. One propensity matched study reported fewer pulmonary complications^24^; however, the other 7 studies did not.^16–18,20,22,23,26^ None of the 4 unmatched observational studies reported a difference between RAMIE and VAMIE approaches.^27,30,31,34^ Most of the studies had a point estimate of effect falling within the 95% confidence interval of the RCT, which may suggest a possible signal that there may be fewer pulmonary complications in RAMIE compared with VAMIE.

None of the 4 US observational studies assessing LOS found a significant difference between RAMIE as compared to VAMIE; 2 were matched and 2 were unmatched studies.^19,22,27,29^ One of these studies compared robot-assisted and laparoscopic transhiatal esophagectomy, which had no difference in LOS.^29^ Nine non-US studies evaluated LOS, of which none demonstrated differences between RAMIE and VAMIE (see Appendix G. Evidence table).^15–18,20,23,24,26,34^ All but 1 of the 9 non-US studies had a LOS with a central tendency (mean or median) greater than 10 days in both study arms,^26^ whereas all US studies had a measure of central tendency of 10 days or less.

Ten studies assessed outcomes for total complications.^15,18,20,22,24,26,27,29,31,34^ One study compared robot-assisted transhiatal and laparoscopic transhiatal esophagectomy.^29^ The remaining studies compared a robot-assisted transthoracic approach to a thoracoscopic approach. Neither the RCT nor the matched and unmatched observational studies found a difference in complications.

Mortality was assessed in 14 studies.^15–20,22–24,26,27,29,31,34^ Mortality was not different in the RCT or the matched and unmatched observational studies. In general, mortality rate was low across all studies.

#### Short-Term: RAMIE compared with Open Esophagectomy

Eight studies comparing RAMIE and open esophagectomy assessed anastomotic leak rate.^14,21,25,27,28,32–34^ The RCT, 2 matched observational studies, and 5 unmatched observational studies reported no difference in leak rate. One observational study utilized the robot for the abdominal portion combined with thoracotomy, which did not demonstrate a difference in anastomotic leak rates, as the technique for creating the anastomosis was the same in both arms of the study.^33^

Of the 2 matched^21,25^ and 3 unmatched observational studies^28,32,34^ assessing RLN palsy, none found a difference between RAMIE and open esophagectomy.

Eight studies assessed pulmonary complications.^14,21,25,27,28,32–34^ The rate of pulmonary complications was lower for RAMIE and open esophagectomy in the RCT.^14^ One matched observation study and 2 unmatched observational studies also reported a lower rate for RAMIE.^25,27,28^ The largest difference was seen in the RCT^14^ but significance was also achieved in the 1 matched observational study^25^ and 2 unmatched observational studies.^27,28^ One matched observational study and 3 unmatched observational studies did not report a difference in pulmonary complications.^21,32–34^

Three US studies evaluated LOS.^19,27,28^ One matched observational study^19^ and an unmatched observational study^28^ demonstrated a shorter time to discharge with RAMIE. The third study (unmatched observational) did not find any differences in LOS between the study arms.^27^ Of the 6 non-US studies that assessed LOS,^14,21,25,32–34^ 2 demonstrated a shorter hospital stay for RAMIE compared with open esophagectomy (see Appendix G. Evidence Table).^32,33^ The central tendency for LOS was greater than 10 days in both arms of the non-US studies except for one.^33^ One out of the 3 US studies had LOS with a central tendency greater than 10 days.^28^

Six studies assessed total complication rate.^14,21,27,28,33,34^ The RCT demonstrated a lower total complication rate with RAMIE.^14^ Additionally, 1 matched observational study^21^ and 1 unmatched study^33^ showed reduced rates of total complications with RAMIE. Of note, the unmatched study compared the utilization of the robot for the abdominal portion with laparotomy (thoracic portion was performed via thoracotomy in both study arms). Three additional unmatched studies reported no difference total complications with RAMIE as compared to open esophagectomy.^27,28,34^

Mortality was assessed in 9 studies.^14,19,21,25,27,28,32–34^ The RCT reported no different in mortality for RAMIE compared with open esophagectomy.^14^ One matched observational study found that RAMIE was associated with a lower mortality compared with open esophagectomy.^25^ The remaining studies did not show a difference in mortality between study arms.

Figure 3 Short-term Post-operative Outcomes

^1^Dotted line separates RCT from the observational studies

^2^Solid line separates the studies comparing RAMIE with VAMIE or RAMIE with open esophagectomy

### Long-term Outcomes

#### Long-term: RAMIE compared with VAMIE or Open Esophagectomy

Figure 4 presents graphically the results of long-term outcomes for recurrence and cancer-free survival. These outcomes were less frequently reported than the intra-operative and short-term post-operative outcomes. These were evaluated in 2 RCTs^14,15^ and 3 observational studies.^24,25,31^ One study reported overall survival instead of cancer-free survival.^19^

The RCT reported no difference in recurrence rate for RAMIE as compared to VAMIE, but a better cancer-free survival.^15^ Recurrence rate was not different in the 1 matched observational study that reported on RAMIE as compared to VAMIE.^24^ For the matched observational study that only reported overall survival, there was no difference between RAMIE and VAMIE.^19^ Cancer-free survival was not different between RAMIE and VAMIE for 1 unmatched observational study.^31^ The one RCT and 2 matched observational studies comparing RAMIE to open esophagectomy did not report differences in either of these long-term outcomes.^14,19,25^

Figure 4 Long-term Outcomes

^1^Dotted line separates RCT from the observational studies

^2^Solid line separates the studies comparing RAMIE with VAMIE or RAMIE with open esophagectomy

### Summary of Findings

In general, OR time for RAMIE was longer than VAMIE and open esophagectomy. Although the RCT comparing RAMIE and VAMIE demonstrated OR times that were not different between study arms, several propensity-matched observational and unmatched observational studies concluded OR times were longer for RAMIE. The majority of studies demonstrated a signal of greater LN harvest with RAMIE compared with VAMIE and open esophagectomy. RAMIE may be associated with less EBL compared with VAMIE, but none of the findings reached statistical significance. Alternatively, RAMIE was associated with less EBL compared with open esophagectomy across the majority of studies.

Regarding short-term post-operative outcomes, the rate of anastomotic leak and RLN palsy did not appear to be different between RAMIE compared with either VAMIE or with open esophagectomy approaches. A difference in outcomes for different approaches (ie, McKeown and Ivor-Lewis esophagectomy) was not identified, and none of the studies reached statistical significance. RAMIE may be associated with slightly fewer pulmonary complications compared with VAMIE based on consistent findings across the majority of studies. The benefit of RAMIE on the rate of pulmonary complications was more apparent compared with open esophagectomy. It is unclear if LOS in the US was shorter with RAMIE compared with VAMIE, as there were too few studies with mixed results to draw a conclusion. In contrast, RAMIE was likely associated with decreased LOS compared with open esophagectomy based on 2 studies,^14,28^ including 1 RCT. RAMIE had similar rates of total complications compared with VAMIE but was associated with decreased total complications when compared with open esophagectomy. Short-term mortality (within 90 days) was similar between RAMIE and VAMIE. Short-term mortality between RAMIE and open esophagectomy was less clear due to differences between studies, but RAMIE likely did not have worse mortality.

With regard to oncologic outcomes, RAMIE may be associated with better cancer-free survival compared with VAMIE. However, this conclusion was based primarily on 1 RCT.^15^ There was no difference between RAMIE and VAMIE for recurrence rate. There was no difference in recurrence rate and disease-free survival between RAMIE and open esophagectomy.

### Certainty of Evidence for Key Question 1

#### RAMIE compared with VAMIE

We judged the certainty of evidence for the outcome of longer OR time and improved lymph node harvest for RAMIE compared with VAMIE as low due to inconsistency and imprecision. We judged the certainty of evidence that there are no differences in EBL and anastomotic leak between RAMIE and VAMIE as moderate due to inconsistency. RLN palsy was determined to be not different with low certainty of evidence based on inconsistency. The certainty of evidence for the outcome of fewer pulmonary complications in RAMIE compared with VAMIE was deemed low due to inconsistency and relatively small estimated effect. The certainty of evidence that there are no differences in LOS or total complications between RAMIE and VAMIE is moderate due to some inconsistency and imprecision due to limited data. We judged the certainty of evidence that there is no difference in mortality between RAMIE and VAMIE as moderate due to some imprecision. Regarding long-term outcomes, we deemed the certainty of evidence that recurrence is not different between RAMIE and VAMIE as very low due to inconsistency, imprecision due to a paucity of studies, and serious study limitations due to large attrition rates in 1 study.^24^ The certainty of evidence that cancer-free survival is longer for RAMIE compared with VAMIE is very low for the same reasons.

#### RAMIE compared with Open Esophagectomy

We judged the certainty of evidence for the outcome of longer OR time for RAMIE compared with open esophagectomy as high. The certainty of evidence of improved lymph node harvest favoring RAMIE was judged to be moderate due to imprecision. We judged the certainty of evidence that EBL is less for RAMIE as high. The certainty of evidence that anastomotic leak is not different between RAMIE and open esophagectomy is moderate due to imprecision. We deemed the certainty of evidence that RLN palsy is not different between RAMIE and open esophagectomy as moderate due to study limitations. The certainty of evidence that RAMIE is associated with a lower rate of pulmonary complications compared with open esophagectomy is deemed to be moderate due to imprecision. We judged the certainty of evidence that LOS is shorter for RAMIE compared with open esophagectomy as very low due to inconsistency and imprecision due to sparsity of data. The certainty of evidence that there are fewer total complications with RAMIE compared with open esophagectomy is moderate due to some imprecision. The certainty of evidence that short-term mortality is not different between RAMIE and open esophagectomy is deemed to be very low due to inconsistency and imprecision. The certainty of evidence that recurrence and cancer-free survival are similar for RAMIE compared with open esophagectomy is very low due to imprecision, paucity of studies, and study limitations.

Table 1 Certainty of Evidence for Key Question 1

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Intra-operative
Operating Room Time | RCT: Low
RAMIE > VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Low
RAMIE > Open | Unmatched observational studies: High | Consistent | Direct | Precise | High
Lymph Node Harvest | RCT: Low
RAMIE >VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Low
RAMIE > Open | Unmatched observational studies: High | Consistent | Direct | Imprecise | Moderate
Estimated Blood Loss | RCT: Low
RAMIE = VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Precise | Moderate
RAMIE < Open | Unmatched observational studies: High | Inconsistent | Direct | Precise | High
Short-term Post-operative
Anastomotic Leak | RCT: Low
RAMIE = VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Precise | Moderate
RAMIE = Open | Unmatched observational studies: High | Consistent | Direct | Imprecise | Moderate
Recurrent Laryngeal Nerve Palsy | RCT: Low
RAMIE = VAMIE | Matched observational studies: Low | Inconsistent | Direct | Precise | Low
RAMIE = Open | Unmatched observational studies: Moderate | Consistent | Direct | Precise | Moderate
Pulmonary Complications | RCT: Low
RAMIE < VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Precise | Low
RAMIE < Open | Unmatched observational studies: High | Consistent | Direct | Imprecise | Moderate
LOS
RAMIE = VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Moderate
RAMIE < Open | Unmatched observational studies: High | Inconsistent | Direct | Imprecise | Very Low
Total Complications | RCT: Low
RAMIE = VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Moderate
RAMIE < Open | Unmatched observational studies: High | Consistent | Direct | Imprecise | Moderate
Mortality | RCT: Low
RAMIE = VAMIE | Matched observational studies: Moderate | Consistent | Direct | Imprecise | Moderate
RAMIE = Open | Unmatched observational studies: High | Inconsistent | Direct | Imprecise | Very Low
Long-term/Oncologic
Recurrence | RCT: Low
RAMIE < VAMIE | Matched observational studies: Moderate | Inconsistent | Direct | Imprecise | Very Low
RAMIE = Open | Unmatched observational studies: High | Inconsistent | Direct | Imprecise | Very Low
Cancer-Free Survival | RCT: Low
RAMIE > VAMIE | Matched observational studies: High | Inconsistent | Direct | Imprecise | Very Low
RAMIE = Open | Unmatched observational studies: High | Consistent | Direct | Imprecise | Very Low

## KEY QUESTION 2 What is the cost-effectiveness of robot-assisted esophagectomy compared to thoracoscopic/ laparoscopic or open esophagectomy for cancer?

No studies evaluated the cost-effectiveness of robot-assisted surgery compared with open or thoracoscopic/laparoscopic surgery for esophagectomy for cancer. Two publications included in their analysis some measure of cost (see Table 2).^17,35^ One was a retrospective cohort study from a single institution in China comparing transthoracic RAMIE with transthoracic VAMIE. The second was an RCT from a single institution in the Netherlands comparing transthoracic RAMIE with open thoracotomy. The RCT was an abstract^35^ published ahead of the full manuscript.^14^ The abstract contains cost data that was not included in the final publication. Both were small studies including approximately 50 patients in the robotic arm.

Table 2 Evidence Table for Cost Studies

Author Year | Study Design, Number of Institutions, Country | Comparison(s) | Number of surgeons | Sample size | Source of cost data | Cost data | Misc Outcomes
Chen, 2019^17^ | Retrospective cohort (propensity matched); Single institution; China | Robot-assisted McKeown esophagectomy vs thoracolaparoscopic McKeown | Single surgical team | Matched; Robot: 54; Lap: 54 | Not stated | Matched; Total expenses (USD): Robot: $25,300±9,000; Lap: $20,800±9,000; (p = 0.009); Expenses/day (USD):; RAMIE: $1,700±700; TLMIE: $1,500±400; (p = 0.028) | Matched; Duration: 187 min (robot) vs 193 min (lap), p=0.30; ICU stay 4.0 days (robot) vs 2.5 days (lap), p=0.14; Total LOS 17.1 days (robot) vs 15.2 days (lap), p=0.33
Van der Sluis, 2018^35^ | RCT; Single institution; Netherlands | Robot-assisted thoracolaparoscopic esophagectomy vs open transthoracic esophagectomy | Two surgeons | Robot: 54; Open: 55 | Not stated | Mean costs:; Robot: €34,892; Open: €39,463; (p = 0.07) | Total OR time 349 min (robot) vs 296 min (open), p<0.001; ICU stay 1 day (robot) vs 1 day (open), p=0.45; Total LOS 14 days (robot) vs 16 days (open), p=0.33

### Summary of Findings

The RCT found no statistical difference in total expenses or cost, while the observational study found the robot-assisted approach was more expensive. There are serious limitations to both of these studies. Neither study included any description of how costs were derived; there is no mention of the time horizon, the financial “perspective” (costs vs charges vs payments), or the methods used to obtain estimates. In particular, with respect to the cost of the robot, it is unclear whether or not these studies included relevant costs such as instrument, maintenance, or depreciation expenses. It is unclear how to compare cost estimates from China to the Netherlands or how these might compare to costs in the US.

Given the paucity of evidence and significant limitations of the available evidence, we are unable to draw any conclusion about the cost-effectiveness of RAMIE compared with VAMIE or open esophagectomy.

## LIMITATIONS

### Publication Bias

We were not able to test for publication bias and can make no conclusions about its possible existence. However, we feel it is extremely unlikely that there exists a high-quality randomized trial of robot-assisted surgery versus other surgical approaches that we did not identify and has similarly escaped detection by all other experts in this field. There is probably a plentitude of observational experiences about robot-assisted therapies from individual institutions that have never been published, and the available literature likely represents only a small fraction of what could be known using observational studies.

### Study Quality

The RCTs were judged to have low risk of bias for short-term outcomes, such as intra-operative and short-term post-operative outcomes, and long-term oncologic outcomes. The observational studies were judged to have moderate risk of bias due to their non-random assignment of treatments for short-term outcomes and high risk of bias for longer-term outcomes. Many of the observational studies did not state how robotic esophagectomy was decided or offered for each patient, causing a risk of selection bias. However, of these studies, 11 were propensity matched, which mitigates the risk of selection bias, reducing the risk from serious to moderate. In terms of long-term outcomes, the high risk of bias is due to the fact that most of the studies calculated survival despite a high attrition rate, with some studies with an attrition rate over 50%.

### Heterogeneity

The 2 general comparisons of the studies were RAMIE compared with VAMIE and RAMIE compared with open esophagectomy. We evaluated these 2 comparison groups separately to account for methodologic heterogeneity. Despite this, there was still significant heterogeneity between the studies. For example, the majority of studies compared transthoracic robot-assisted surgery to open or other minimally invasive approaches, but there are several transthoracic methods (eg, Ivor-Lewis and McKeown esophagectomies) and several hybrid combinations, such as utilizing the robot for the transthoracic portion combined with laparotomy or laparoscopy for the abdominal portion. Further, there are differences between studies with regard to certain techniques, such as creation of the anastomosis, patient positioning, and port placement, that may have an impact on outcomes.

In addition to the variety of procedures performed, certain outcomes were also measured differently across studies. For example, with regard to lymph node harvest, some studies performed a 2-field or 3-field lymphadenectomy. Similarly, some studies reported lymph nodes harvested from specific sites (eg, right and left RLN lymph nodes). RAMIE may have some benefit in terms of lymph node harvest in these particular areas, but it was not reported consistently across studies. Another outcome that was heterogeneous across studies is total complications. While many studies used validated tools such as the Clavien-Dindo classification to define severity of complications, many did not. There was even variability within studies that used the Clavien-Dindo classification because select studies reported grade ≥3 complications while others reported complications that were ≥2. Moreover, many studies classified the post-operative complications into categories and listed the specific complications and frequencies within these categories; however, a handful of studies grouped all complications into one measurement without defining which complications were included. Furthermore, studies did not give specifics, in general, on how complications were treated, like how anastomotic leaks were managed for the different approaches.

### Applicability of Findings to the VA Population

None of the included studies were specific to VA populations. The applicability of these results to VA populations may depend on both the similarity of the patients studied to VA patients and the experience of the surgical teams using the robot to VA surgical team experience. However, the benefits for the robot-assisted approach may still be realized despite patient-level differences (VA patient population has greater burden of comorbidities than the general population), which will need to be confirmed in future studies. Robot-assisted procedures are gaining popularity in thoracic surgery, and the adoption of this platform for esophagectomy will likely translate well into the VA setting. Our group, in conjunction with another VA research team, is in the early stages of utilizing VA NSQIP data to assess the frequency and trends of robot-assisted surgery for esophagectomy in Veterans as well as analyze its association to clinical outcomes.

### Research Gaps/Future Research

Several research gaps are apparent. First, there are numerous surgical techniques for performing an esophagectomy (ie, Ivor-Lewis, McKeown, transhiatal, thoracoabdominal); any combination of robot-assisted, open, or minimally invasive approaches can be utilized. Often, tumor characteristics, such as size and location (upper, mid-, or lower esophagus), dictate which approach or combination is used. We focused on comparing robot-assisted surgery for the thoracic portion of the procedure. However, even when grouping studies that performed a transthoracic esophagectomy, certain outcomes like anastomotic leak might not be generalizable depending on where the anastomosis was located (eg, intrathoracic anastomosis for Ivor-Lewis esophagectomy or cervical anastomosis for McKeown esophagectomy). Therefore, determining the influence of the robot-assisted approach in comparison to other techniques is difficult to disentangle when RCTs or well-designed, matched studies are few.

Additionally, the robotic platform can be used in various stages of an esophagectomy (thoracic or abdominal portions). Na et al,^36^ which was not included in our review, performed a propensity-matched analysis comparing hybrid RAMIE (robot for the thoracic portion combined with laparotomy) with total RAMIE (ie, thoracic and abdominal portions performed with robot). There were no differences in clinical outcomes between approaches; however, the small sample size limited the comparisons. Ideally, studies like this, but with a larger number of patients, could help elucidate differences between specific robotic uses within techniques, such as the abdominal portion in this example. In fact, the Society of Thoracic Surgeons (STS) National Database has worked to expand patient follow-up to 5 years and to include specifics on the various types of approaches, which will allow for more detailed comparisons in the future.

Second, regional variations of surgical practice and esophageal cancer epidemiology exist. The predominant histologic type of esophageal cancer in East Asian countries is squamous cell carcinoma while adenocarcinoma predominates in the US.^37–39^ The 5-year survival is less than 25% between the 2 subtypes, but the risk factors differ and underscore important clinical variation in patient populations.^38,39^ For example, gastroesophageal reflux disease and obesity are risk factors for adenocarcinoma, while smoking, alcohol consumption, and nutritional deficiencies are risk factors for squamous cell carcinoma.^37–39^ Further, East Asian countries in general have a higher incidence of esophageal cancer and thus higher surgical volume.^37–39^

Third, in addition to understanding the relationship of clinical outcomes for patients, the surgeon’s physical experience is relevant. The robotic platform has demonstrated improved ergonomics and less musculoskeletal complaints from surgeons compared with open and other minimally invasive surgical techniques, but this has not been universally observed.^40^ There is evidence that a prolonged time sitting at the robot-assisted console may add physical challenges. The physical impact of minimally invasive versus open surgery on the surgeon is still debated. Physical discomfort and symptoms of poor posture have been reported with minimally invasive surgery as compared to open surgery.^41,42^ However, objective intraoperative measurement of surgeon posture suggests open surgery is more demanding for the neck and trunk.^43^ Research is needed to assess detailed quality of life, assessment of chronic physical injuries, and longevity of operating compared across these approaches.

Fourth, the learning curve likely has an impact on certain outcomes like OR time, blood loss, and intra-operative complications. Its influence on reported outcomes in the literature is hard to discern, as the majority of studies fail to comment on the previous robotic experience or if a learning curve was specifically present. This learning curve is typically present with most evolving surgical technology;. However, the influence of the learning curve should lessen with time and experience.^44^ Therefore, the learning curve may be a potential factor in our findings.

Fifth, there is a lack of high-quality evidence demonstrating the long-term and oncologic benefits, or risks, of RAMIE. The majority of studies comparing RAMIE focus on intra-operative and post-operative outcomes. Intra-operative events have a direct impact on short-term outcomes and potentially an indirect influence on long-term functional status and cancer control. However, new data suggests anastomotic leak does not compromise long-term outcomes or oncological control.^45^ Two RCTs, 1 comparing RAMIE to VAMIE^15^ and another comparing RAMIE to open esophagectomy,^14^ evaluated recurrence and disease-free survival with adequate follow-up. However, these were relatively small studies (n=192 and n=99, respectively). Several observational studies that assessed long-term oncologic outcomes were small and had large attrition. To that end, RAMIE is gaining popularity and more cases are being performed each year, so within several years there may be large studies with adequate follow-up that become available.

Sixth, there is a paucity of studies directly comparing cost between RAMIE and other comparable approaches. Only 2 studies had some measure of cost, but both came from different countries and practice settings and do not generalize well to cost in the US. There is a need for standardized methods to assess cost – which applies to all robot-assisted operations, (ie, analytics, consistent definitions of cost, how upfront capital was accounted for, how to adjust for training staff, etc). Along these lines, formal cost-effectiveness studies that weigh the benefits and risks along with cost are needed.

Further, the recent Laparoscopic Approach to Cervical Cancer trial compared minimally invasive surgery, including laparoscopic and robotic, to open surgery in early-stage cervical cancer and found worse survival in the minimally invasive group.^46^ In response, the FDA issued a warning: “The relative benefits and risks of surgery using robotically-assisted surgical devices compared with conventional surgical approaches in cancer treatment have not been established.” The FDA encouraged research on robotic surgery, emphasizing impact on long-term clinical and oncologic outcomes. Careful analysis is warranted.

## CONCLUSIONS

In summary, esophagectomy is a complex procedure with a high rate of morbidity, and while the robot-assisted approach has the potential to provide beneficial outcomes, current data is too limited to provide definitive conclusions. Future research should include RCTs or well-designed prospective matched studies with adequate power and follow-up to assess long-term as well as oncologic outcomes in patients undergoing robot-assisted surgery for esophageal cancer, including determination of risks. Additional work should also weigh the financial differences of the robot-assisted esophagectomy relative to the clinical advantages and disadvantages.