# INTRODUCTION

Worldwide adoption of robot-assisted surgery continues to increase, particularly for cancer and thoracic operations. Esophageal cancer is the seventh most common cancer diagnosis globally each year, with an estimated 572,000 new cases in 2018.^1^ Esophagectomy is an important component of esophageal cancer treatment and is performed using open, conventional minimally invasive techniques (thoracoscopic and laparoscopic), or robot-assisted approaches. In 2016, there were over 1,800 robotic esophagectomies performed worldwide, a 9-fold increase from those performed in 2009.^2^

Historically, open esophagectomy (OE) is the standard surgical approach for esophageal cancer and is often combined with perioperative chemotherapy or chemoradiation for more advanced disease.^3,4^ However, OE is a technically difficult operation with an associated morbidity and mortality of nearly 50% and 5%, respectively.^5^ Minimally invasive approaches have been adopted, combining laparoscopic and thoracoscopic techniques with a handful of trials demonstrating fewer post-operative complications and similar oncologic outcomes.^6–8^

Robot-assisted minimally invasive esophagectomy (RAMIE) offers additional benefits to standard minimally invasive approaches due to the 540 degrees of wrist articulation, three-dimensional perspective, and greater magnification which may allow for a more meticulous dissection.^9,10^ Despite the rapid adoption of RAMIE, several questions remain about its utility compared to OE and other minimally invasive approaches, especially with regard to long-term oncologic outcomes. Another important consideration is the economics of the robotic platform, which requires an upfront investment and costs for annual maintenance, instruments, staff and training, and infrastructure upgrade.

Individual studies and systematic reviews comparing RAMIE to MIE or OE have methodological variations and inconsistent reporting of oncologic and surgery-related outcomes. This is complicated further by the multiple approaches for esophagectomy (Ivor-Lewis, McKeown, and transhiatal) as well as determining if the benefit of the robot lies in the abdominal or thoracic phase of a multi-field esophagectomy.

Robot-assisted surgery for esophageal cancer is being increasingly used, and it is imperative to examine how it compares to open and other minimally invasive approaches, with an emphasis on long-term oncologic outcomes. We have conducted a systematic review to help clinicians, patients, and policymakers weigh these approaches in patients undergoing esophagectomy for cancer.

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Dr. Mark Wilson, National Director of Surgery, and Dr. William Gunnar, Director, National Center for Patient Safety, Veterans Health Administration. Key questions were then developed with input from the topic nominator, the ESP coordinating center, the review team, and the technical expert panel (TEP).

The Key Questions were:

KQ1 What is the clinical effectiveness of robot-assisted esophagectomy compared to thoracoscopic/laparoscopic or open esophagectomy for cancer?
KQ2 What is the cost-effectiveness of robot-assisted esophagectomy compared to thoracoscopic/laparoscopic or open esophagectomy for cancer?

The review was registered in PROSPERO: CRD42020198907.

## SEARCH STRATEGY

We conducted broad searches using terms relating to “robotic surgery” or “esophagectomy” or “cancer.” We searched PubMed (1/1/13-5/5/20), Cochrane (1/1/13-5/11/20), Ovid Medline (1/1/13-5/5/20), and Embase (1/1/13-5/6/20). Prior to 2013, robot-assisted procedures for esophagectomy were not widely being performed and many surgeons were still in the early so-called “learning curve”. As such, our technical expert panel considered evidence from studies published prior to the year 2013 to be insufficiently relevant to modern practice. See Appendix A for complete search strategy.

## STUDY SELECTION

Three team members working in pairs (MM/MG and MM/RS) independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by 5 team members working in pairs (MM/MG; MM/MMG; MM/PT; and MM/RS). All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members (MM and MD) with any disagreements resolved through discussion.

Studies were included at either the abstract or the full-text level if they were randomized clinical trials (RCTs) or observational studies comparing robot-assisted surgery with either thoracoscopic/laparoscopic or open surgical approaches for the included surgical procedure. The approach in the robotic arm (eg, Ivor-Lewis, McKeown, transthoracic, transhiatal) needed to be similar to the comparison arm to be included. We included all RCTs regardless of outcomes studied or sample size. Observational studies were subjected to additional selection criteria. Observational studies with less than 10 subjects in either arm of the study were excluded. Additionally, observational studies from the same data source, either large databases or single institutional databases, were considered to have a large overlap if >50% of the same subjects were included in multiple studies or if there was >50% overlap in the enrollment period. In this instance, the publication with the most recent data and the most outcomes of interest was included. We also included publications of cost-effectiveness models that compared robot-assisted surgery with thoracoscopic/laparoscopic or open surgical approaches.

## DATA ABSTRACTION

Data extraction was completed in duplicate (MM/MD; MM/MMG; and MM/MG). Data from a non-English study was extracted by 1 member of the research team (MMG) with assistance from an English-speaking physician with extensive experience in systematic reviews whose native language is the non-English language of interest. All discrepancies were resolved with full group discussion. We abstracted data on study design and pre-operative patient and tumor characteristics, intra-operative outcomes, short-term outcomes, long-term clinical/oncologic outcomes, and data needed for the Cochrane Risk of Bias tool or Cochrane Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I).

Intra-operative outcomes of interest included the duration of the operation (OR time), estimated blood loss (EBL), and number of lymph nodes (LN) harvested. The short-term outcomes of interest included anastomotic leak, recurrent laryngeal nerve (RLN) palsy and/or hoarseness, pulmonary complications (ie, pneumonia, pleural effusion), duration of hospitalization (length of stay [LOS]), total post-operative complications, and mortality within 90 days. Long-term oncologic outcomes of interest were cancer recurrence and cancer-free survival. Of note, we used total OR time when reported. For LOS, since non-US studies have notably longer LOS (more than a week typically), we decided to only plot US-based studies in our analysis figures. For total post-operative complications, we reported this outcome if it was specifically provided or, if not, we reported major complications if available. Continuous outcomes were analyzed using the mean or median along with a measure of dispersion (standard deviation, inter-quartile range) to calculate the difference and 95% confidence interval between arms. For binary outcomes, the number of subjects with the outcome was collected and a risk difference was derived with its 95% confidence interval.

## QUALITY ASSESSMENT

RCTs were assessed for quality (risk of bias) with the Cochrane Risk of Bias tool.^11^ This tool requires an assessment of whether a study is at high or low (or unknown) risk of bias in 7 domains: random sequence generation, allocation concealment, blinding of participants and personnel, blinding of outcome assessment, incomplete outcome data, selective outcome reporting, and other (See Appendix C for tool; Appendix E for table). We used the Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I) for observational studies.^12^ This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix D for tool; Appendix F for table). Since observational studies are not required to have published an a priori protocol, we operationalized the last domain (bias in selection of the reported result) as requiring that studies report the most common variables.

## DATA SYNTHESIS

Because there was a paucity of RCTs, we did not conduct a meta-analysis of trials. The observational studies were too clinically heterogeneous to support meta-analysis; hence, our synthesis is narrative.

## RATING THE BODY OF EVIDENCE

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^13^ GRADE assesses the certainty of the evidence based on the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## PEER REVIEW

A draft version of the report was reviewed by technical experts and clinical leadership. Reviewer comments and our responses are documented in Appendix B.