# APPENDIX I CITATIONS FOR EXCLUDED PUBLICATIONS

## Intervention (n=6)

1 Luketich JD, Pennathur A, Franchetti Y, . Minimally invasive esophagectomy: results of a prospective phase II multicenter trial-the eastern cooperative oncology group (E2202) study. Ann Surg. 2015;261(4):702–707.25575253
2 Miyasaka D, Okushiba S, Sasaki T, . Clinical evaluation of the feasibility of minimally invasive surgery in esophageal cancer. Asian J Endosc Surg. 2013;6(1):26–32.23116427
3 Mu J, Yuan Z, Zhang B, . Comparative study of minimally invasive versus open esophagectomy for esophageal cancer in a single cancer center. Chin Med J (Engl). 2014;127(4):747–752.24534234
4 Romero D. Hybrid minimally invasive surgery overtakes open surgery. Nat Rev Clin Oncol. 2019;16(3):144.
5 Xie MR, Liu CQ, Guo MF, . Short-term outcomes of minimally invasive Ivor-Lewis esophagectomy for esophageal cancer. Ann Thorac Surg. 2014;97(5):1721–1727.24657031
6 Yanasoot A, Yolsuriyanwong K, Ruangsin S, . Costs and benefits of different methods of esophagectomy for esophageal cancer. Asian Cardiovasc Thorac Ann. 2017;25(7–8):513–517.28871799

## Comparison (n=3)

1 Mori K, Yamagata Y, Aikou S, . Short-term outcomes of robotic radical esophagectomy for esophageal cancer by a nontransthoracic approach compared with conventional transthoracic surgery. Dis Esophagus. 2016;29(5):429–434.25809390
2 Na KJ, Park S, Park IK, . Outcomes after total robotic esophagectomy for esophageal cancer: a propensity-matched comparison with hybrid robotic esophagectomy. J Thorac Dis. 2019;11(12):5310–5320.32030248
3 Worrell SG, Bachman KC, Sarode AL, . Minimally invasive esophagectomy is associated with superior survival, lymphadenectomy and surgical margins: propensity matched analysis of the National Cancer Database. Dis Esophagus. 2020.

## Small sample size (n=1)

1 Raja K. Minimally invasive esophagectomy after neoadjuvant chemoradiotherapy using cross regimen for locally advanced esophageal cancer. Gut. 2019;68:A69.

## Not original research (n=1)

1 Inderhees S, Dubecz A. [Hybrid minimally invasive esophagectomy for esophageal cancer-MIRO trial]. Chirurg. 2019;90(8):677.31127335

## Duplicate or studies with a large overlap of patients from the same data source (n=11)

1 Li B, Li Z. Early results of robot assisted esophagec-tomy compared with conventional thoracoscopic approach for esophageal cancer: A randomized clinical trial. Diseases of the Esophagus. 2018;31:2.
2 Tagkalos E, Goense L, Hoppe-Lotichius M, . Robot-assisted minimally invasive esophagectomy (RAMIE) compared to conventional minimally invasive esophagectomy (MIE) for esophageal cancer: a propensity-matched analysis. Dis Esophagus. 2020;33(4).
3 Lin Y, Deng H. Comparison of short-term outcomes between RAMIE and VAMIE in treatment middle thoracic esophageal cancer. Diseases of the Esophagus. 2018;31:112.
4 Grimminger PP, Tagkalos E, Hadzijusufovic E, . Change from Hybrid to Fully Minimally Invasive and Robotic Esophagectomy is Possible without Compromises. Thorac Cardiovasc Surg. 2019;67(7):589–596.30216947
5 Deng HY, Huang WX, Li G, . Comparison of short-term outcomes between robot-assisted minimally invasive esophagectomy and video-assisted minimally invasive esophagectomy in treating middle thoracic esophageal cancer. Dis Esophagus. 2018;31(8).
6 Halpern AL, Friedman C, Torphy RJ, . Conversion to open surgery during minimally invasive esophagectomy portends worse short-term outcomes: an analysis of the National Cancer Database. Surg Endosc. 2019.
7 Meredith K, Blinn P, Maramara T, . Comparative outcomes of minimally invasive and robotic-assisted esophagectomy. Surgical Endoscopy. 2020;34(2):814–820.31183790
8 Van Der Sluis PC, Van Der Horst S, May A, . Robot-assisted minimally invasive esophagectomy versus open transthoracic esophagectomy for esophageal cancer: A randomized controlled trial. Surgical Endoscopy. 2018;32:S475.
9 Weksler B, Sullivan JL. Survival After Esophagectomy: A Propensity-Matched Study of Different Surgical Approaches. Ann Thorac Surg. 2017;104(4):1138–1146.28760463
10 Yerokun BA, Sun Z, Yang CJ, . Minimally Invasive Versus Open Esophagectomy forEsophageal Cancer: A Population-Based Analysis. Ann Thorac Surg. 2016;102(2):416–423.27157326
11 Yun JK, Lee IS, Gong CS, . Clinical utility of robot-assisted transthoracicesophagectomy in advanced esophageal cancer after neoadjuvant chemoradiation therapy. J Thorac Dis. 2019;11(7):2913–2923.31463120

## Unavailable (n=1)

1 Götzky K, Jähne J. [Minimally invasive esophagus resection: Results of a prospective multicenter study]. Chirurg. 2015;86(9):898.26223670