# APPENDIX H OPERATIVE TECHNIQUES OF INCLUDED STUDIES

Study | Study Arm | Approach | Abdomen | Chest | Anastomosis
Chao 2018^16^ | RAMIE | McKeown | Laparoscopic | Robotic | Circular stapled; cervical
Chao 2018^16^ | VAMIE | McKeown | Laparoscopic | VATS | Circular stapled; cervical
Chen 2019^17^ | RAMIE | McKeown | NR | Robotic | Circular stapled; cervical
Chen 2019^17^ | VAMIE | McKeown | Laparoscopic | VATS | Circular stapled; cervical
Deng 2018^18^ | RAMIE | McKeown | Robotic | Robotic | Circular stapled or handsewn; cervical
Deng 2018^18^ | VAMIE | McKeown | Laparoscopic | VATS | Circular stapled or handsewn; cervical
Espinoza-Mercado 2019^19^ | RAMIE | NR | NR | NR | NR
Espinoza-Mercado 2019^19^ | VAMIE | NR | NR | NR | NR
Espinoza-Mercado 2019^19^ | Open | NR | NR | NR | NR
Gong 2020^34^ | RAMIE | McKeown | Robotic | Robotic | Circular stapled; cervical
Gong 2020^34^ | VAMIE | McKeown | Laparoscopic | VATS | Circular stapled; cervical
Gong 2020^34^ | Open | McKeown | Laparotomy | Thoracotomy | NR
He 2018^20^ | RAMIE | McKeown | Robotic | Robotic | End to side circular stapled; cervical
He 2018^20^ | VAMIE | McKeown | Laparoscopic | VATS | End to side circular stapled; cervical
He 2020^15^ | RAMIE | McKeown | Robotic | Robotic | Cervical
He 2020^15^ | VAMIE | McKeown | Laparoscopic | VATS | Cervical
Jeong 2016^21^ | RAMIE | McKeown | Laparotomy | Robotic | Cervical
Jeong 2016^21^ | Open | Ivor-Lewis or McKeown | Laparotomy | Thoracotomy | Cervical or thoracic
Meredith 2019^27^ | RAMIE | Ivor-Lewis | NR | NR | NR
Meredith 2019^27^ | VAMIE | Ivor-Lewis | NR | NR | NR
Meredith 2019^27^ | Open | Ivor-Lewis | NR | NR | NR
Motoyama 2019^30^ | RAMIE | Ivor-Lewis | NR | Robotic | NR
Motoyama 2019^30^ | VAMIE | Ivor-Lewis | NR | VATS | NR
Naffouje 2019^22^ | RAMIE | Ivor-Lewis | NR | NR | NR
Naffouje 2019^22^ | VAMIE | Ivor-Lewis | NR | NR | NR
Osaka 2018^32^ | RAMIE | NR | NR | Robotic | NR
Osaka 2018^32^ | Open | NR | NR | Thoracotomy | NR
Park 2016^31^ | RAMIE | 90% McKeown; 10% Ivor-Lewis | 58% robotic; 42% open* | Robotic | 90% cervical; 10% thoracic
Park 2016^31^ | VAMIE | 81% McKeown; 19% Ivor-Lewis | 49% laparoscopic; 51% open* | VATS | 81% cervical; 19% thoracic
Rolff 2017^33^ | RAMIE | Ivor-Lewis | Robotic | Thoracotomy | NR
Rolff 2017^33^ | Open | Ivor-Lewis | Laparotomy | Thoracotomy | NR
Sarkaria 2019^28^ | RAMIE | 62/64 Ivor-Lewis; 2/64 McKeown | NR | NR | NR
Sarkaria 2019^28^ | Open | 103/106 open Ivor-Lewis; 3/106 thoracoabdominal | NR | NR | NR
van der Sluis 2019^14^ | RAMIE | McKeown | Laparotomy | Robotic | End to side handsewn; cervical
van der Sluis 2019^14^ | Open | McKeown | Laparotomy | Thoracotomy | End to side handsewn; cervical
Tagkalos 2019^23^ | RAMIE | Ivor-Lewis | Robotic | Robotic | Circular stapled; intrathoracic
Tagkalos 2019^23^ | VAMIE | Ivor-Lewis | Laparoscopic | VATS | Circular stapled; intrathoracic
Washington 2019^29^ | RAMIE | Transhiatal | Robotic | NA | Cervical
Washington 2019^29^ | VAMIE | Transhiatal | Laparoscopic | NA | Cervical
Yang 2019^24^ | RAMIE | McKeown | Robotic | Robotic | Cervical
Yang 2019^24^ | VAMIE | McKeown | Laparoscopic | VATS | Cervical
Yun 2019^25^ | RAMIE | 57.1% Ivor-Lewis; 42.9% McKeown | Robotic or Laparoscopic | Robotic | Circular stapled; cervical
Yun 2019^25^ | Open | 54.4% Ivor-Lewis; 45.6% McKeown | Laparotomy | Thoracotomy | Circular stapled; cervical
Zhang 2019^26^ | RAMIE | Ivor-Lewis | Robotic | Robotic | End to end both circular stapled + handsewn; intrathoracic
Zhang 2019^26^ | VAMIE | Ivor-Lewis | Laparoscopic | VATS | End to end circular stapled; intrathoracic