# APPENDIX G EVIDENCE TABLES

## Patient Characteristics and Intra-operative Outcomes

## Short- and Long-term Outcomes