# APPENDIX F QUALITY ASSESSMENT FOR INCLUDED OBSERVATIONAL STUDIES

Author, year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result | Other source of bias
Chao 2018^16^ | Low | Moderate; RAMIE offered to all patients after 2014, but it was only partially insured while MIE was fully covered | Low | Low | Low | Low | Low | n/a
Chen 2019^17^ | Low | Moderate; Unknown how intervention offered; propensity matched for pre-op factors | Low | Low | Low | Low | Low | n/a
Deng 2019^18^ | Low | Low; Offered RAMIE & VAMIE, patients chose on their own will | Low | Low | Low | Low | Low | n/a
Espinoza-Mercado 2019^19^ NCDB | Low | Moderate; Unknown how intervention offered; propensity matched for pre-op factors | Moderate; Unable to differentiate the surgical approach – transhiatal, IL, McKeown | Low | Low | Low | Low | n/a
Gong 2020^34^ | Serious Clinical stage and neoadjuvant treatment were different between treatment arms | Serious; Unknown who was offered which technique | Low | Low | Low | Low | Low | n/a
He 2018^20^ | Low | Moderate; Unknown how intervention offered; propensity matched for pre-op factors | Low | Low | Low | Low | Low | n/a
Jeong 2016^47^ | Low | Moderate; RAMIE recommended for specific indications (eg, low clinical stage); however, the propensity matched for most of these factors | Low | Low | Low | Low; Standardized tools were used to assess pain and delirium | Low | n/a
Meredith 2019^27^ | Serious; No p-values provided | Serious; Unknown how intervention offered | Low | Low | Low | Low | Low | n/a
Motoyama 2019^30^ | Low | Serious; Unknown how intervention offered; between 2014 and 2018. RAMIE was not covered by insurance; so only those who could pay underwent robot during that time period | Low | Low | Low | Low | Moderate; Do not report several outcomes | n/a
Naffouje 2019^22^ NSQIP | Low | Moderate Unknown how intervention offered; propensity matched for pre-op factors | Low | Low | Low | Low | Low | n/a
Osaka 2018^32^ | Moderate; List very few patient characteristics | Serious; Unknown who was offered RAMIE. Do not explicitly state what the “criteria for robot” are that they used to match open surgery | Low | Low | Low | Low | Moderate; Do not report several outcomes that are given in similar studies | n/a
Park 2016^48^ | Low | Serious; Unknown who RAMIE was offered to | Low | Low | Short-term outcomes: Low; Long-term outcomes: Serious (>50% lost to follow up at 5-year outcomes) | Low | Serious; Several outcomes of high importance not included (ie, LOS). | n/a
Rolff 2017^33^ | Serious; Very few patient characteristics, no clinical oncologic data, etc | Moderate; Intervention depended on date of operation and robot availability. However, large tumors and BMI >35 were initially precluded from robot. This changed early in the study and the restriction on BMI was relaxed | Low | Low | Low | Low | Moderate; Few outcomes given | n/a
Sarkaria 2019^28^ | Low | Moderate; Receipt of RAMIE depended on which surgeon the patient was referred to | Low | Low | Low | Moderate; Subjective data collected by research staff. Used validated tools/questionnaires | Low | n/a
Tagkalos 2019^23^ | Low | Moderate; Unknown how intervention offered; propensity matched for pre-op factors | Low | Low | Low | Low | Low | n/a
Washington 2019^29^ | Serious; Very few patient characteristics listed | Moderate; Receipt of RAMIE was dependent on robot availability and other factors. Transition was made to all robot, so it hints that most patients toward the end of the study were all offered RAMIE. No propensity matching. | Low | Low | Low | Low | Serious; Missing some outcomes compared to similar studies | n/a
Yang 2019^24^ | Low | Low; Some patients were randomized as part of an ongoing trial, and others were given the choice and selected on their own will. Authors state there was no intended selection bias toward one option versus the other. Patients were also propensity matched. | Low | Low | Short-term outcomes: Low; Long-term outcomes: Serious; Relatively short follow-up time; authors point out that their follow up time was adequate for time to recurrence as opposed to overall survival analysis | Low | Low | n/a
Yun 2019^25^ | Low | Moderate; Patients were able to decide between open or robot, but bulky tumors or large metastatic lymph nodes were contraindications to RAMIE; cohorts were adjusted with propensity score inverse probabilities | Low | Low | Short-term outcomes: Low; Long-term outcomes: Serious Large loss to follow up, particularly in the robot arm | Low | Low | n/a
Zhang 2019^26^ | Moderate; Even after PSM, TNM stage is worse for Robot cohort, but not significant | Moderate; Patients were able to decide between open or robot, but between 2014 and 2015 – part of the enrollment period – RAMIE was not performed; propensity matching performed | Low | Low | Low | Low | Low | n/a