# APPENDIX E QUALITY ASSESSMENT FOR INCLUDED RCT STUDIES

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting | Other sources of bias
He, 2020^15^ | ⚪ | ⯋ | ⯋ | ⯋ | Short-term:; ⚪; Long-term:; ⚪ | ⚪ | ⚪
van der Sluis, 2019^14^ | ⚪ | ⚪ | ⚪; *Patients blinded to intervention | ⚫; Trial coordinators recorded daily outcomes | Short-term:; ⚪; Long-term:; ⚪ | ⚪ | ⚪

⚪ = low risk of bias ⚫ = risk of bias ⯋ = unknown

* low risk of bias for primary outcomes (all-cause mortality and amputation-free survival, but high risk of bias for secondary outcome