# APPRENDIX B PEER REVIEWER COMMENTS AND AUTHOR RESPONSES

Reviewer comments | | | | | | | Authors Responses
Yes - Yang L, Wang T, Weidner TK, Madura JA 2nd, Morrow MM, Hallbeck MS. Intraoperative musculoskeletal discomfort and risk for surgeons during open and laparoscopic surgery. Surg Endosc. 2020 Oct 20. doi: 10.1007/s00464-020-08085-3. Epub ahead of print. PMID: 33083930.33083930 | | | | | | | Thank you for this reference. We have included it in our discussion. This study highlights the physical burdens of open surgery and the potential benefit of laparoscopic and robotic surgery.
Outcomes of esophagectomy are known to correlate with certain preoperative variables including tumor location, stage, neoadjuvant therapy and with intraoperative technique such as MIS and/or robot used for thoracic, abdominal, both, and anastomotic location/technique. Appendix G provides insightful summaries of matching strategies used in included studies. Would clearer reference to matching of critical factors and citation of Appendix G in the Discussion (or Methods) section be advisable? | | | | | | | Thank you for your suggestion. We included a reference to Appendix G in the discussion. We agree that these are important variables to consider. Many of the studies corrected for these factors with propensity matching. Also, the majority of studies included in this review utilized the same approach (McKeown or Ivor-Lewis) in the study arms but utilized a different technique (robot vs open or MIE). Of note, we used inclusion criteria to identify studies where the robotic approach was the within study comparison.
This paper appears to be well written and researched. It has included the review of major literature in the adaption of the robotic platform to the esophagectomy. Especially for use in the VA, many centers already have the Da Vinci Robot, so it makes sense to try to utilize it for Esophagectomy without a huge cost burden. However, there are some issues that may arise especially with esophageal cancer volume and robotics in various centers. I; Regarding study selection, only studies with greater than 10 patients per arm were included when it comes to observational studies. Why not include studies with less than 10? | | | | | | | Case series with less than 10 subjects in each study arm were deemed too high risk for potential biases because of the differences in patient level factors and tumor factors. Differences (or the lack of) between study groups in these smaller studies would be more potentially underpowered and may lead to incorrect conclusions. Also, only one study (including at the abstract and full text review) was identified with a study arm with less than 10 patients (N=4) in the abstract and full text screening phases.
Next, I had a question regarding anastomotic leak when comparing RAMIE with VAMIE or open. It states here at there were three studies with anastomotic leak difference between Open and RAMIE. Did this make a difference in outcomes? Were the leaks managed differently? And were the leaks with RAMIE less morbid and managed differently than the Open patients? Also, did this change adjuvant systemic therapy at all? | | | | | | | The draft had a typo regarding this. No studies comparing OE with RAMIE found a difference in anastomotic leak rate. This has been corrected. These are great questions, but unfortunately the published studies do not go into that level of detail. This was added to our limitations paragraph.
Page 8/line 11: why is the US specifically referenced for LOS in RAMIE vs VAMIE? is there an LOS difference outside of the US? | | | | | | | There are international variations in length of stay with many non-US studies allowing very prolonged hospital stays based on a variety of factors (cultural, health care system, etc). As such, the association of the procedure approach (robot) would differ based on the origin of the study. Thus, for this one outcome we elected to restrict the analysis to USA-only studies, as we judged these would be more relevant to the VA population and system.
9/15: “there are no differences LOS…”, consider inserting the word WITH before LOS. | | | | | | | Thank you noticing this error. It has been corrected.
13/21: abbreviation for open esophagectomy needed (OE) | | | | | | | The requested edit was made.
13/25: i feel this paragraph implies that minimally invasive approaches may be less technically demanding than OE, which is untrue. minimally invasive approaches are much more technically demanding but have fewer postoperative complications. Possibly removing the wording that “OE is a technically difficult operation”, or just that esophagectomy is a technically difficult operation whether done open or by minimally invasive approaches. | | | | | | | We agree. Thank you for making this important point. Esophagectomy is a technically challenging operation and minimally invasive techniques require additional expertise to be proficient. We have corrected this to convey that esophagectomy, regardless of approach or technique, is technically difficult.
23/18: when it is described that the studies reported a difference in leak rate, it is not obvious which had lower leak rates (RAMIE or OE). Because in the summary it is stated that there is no difference, possibly it is meant to state “…observational studies reported NO difference in leak rate.”? | | | | | | | Thank you noticing this discrepancy. We have corrected it in the manuscript.
36/5: “…which was not an include in our review…”, possibly change to “which was not INCLUDED in our review”. | | | | | | | Thank you for careful review. We have made the requested change.
36/33: I find it odd that there is a reference that shows increased physical discomfort and symptoms or poor posture with laparoscopy when compared with open surgery, my understanding is the opposite. Possibly more references need to be included or the statement can be deemed as an ongoing controversy with unclear understanding. One such is below.; Yang L, Wang T, Weidner TK, Madura JA 2nd, Morrow MM, Hallbeck MS. Intraoperative musculoskeletal discomfort and risk for surgeons during open and laparoscopic surgery. Surg Endosc. 2020 Oct 20. doi: 10.1007/s00464-020-08085-3. Epub ahead of print. PMID: 33083930.33083930 | | | | | | | Thank you for your comments and your understanding of the existing controversy. We agree with you that typically laparoscopy should help to prevent musculoskeletal problems for surgeons. However, several questionnaire studies (which we referenced in our report) consistently found higher rates of physical discomfort with minimally invasive surgery compared to open. In contrast, the study you shared has objective data regarding surgeon posture and is an important aspect for this ongoing debate. We appreciate your insight in this matter and certainly it is unclear what role laparoscopy plays in minimizing surgeon discomfort.
This is an incredibly detailed and thoughtful review of the many potential clinical and economic benefits and risks of robotic esophagectomy compared to non-robotic approaches. There is clearly limited data from which the authors had to draw conclusions with only 2 RCTs and a total of 20 publications out of 390 potential papers that met inclusion criteria. Unfortunately, there is also tremendous diversity in terms of cancer epidemiology and with regards to surgical approach and technique. This heterogeneity is dizzying and makes it near impossible to draw conclusions from any comparisons across studies. This is well stated by the authors who comment that it is “difficult to disentangle” the impact of the robot from the various other techniques. That said, the authors should be commended for the rigorousness of their methodology. Frustratingly, their ability to draw meaningful conclusions is quite limited by the quality of publications, inconsistency, imprecision, bias, and heterogeneity. The section on research gaps and future research is the highlight of the paper. | | | | | | | Thank you for those encouraging comments. We agree that the heterogeneity among the studies and paucity of RCTs were limitations and are hopeful that more data will soon emerge so that we can make definitive conclusions with a high level of certainty
While reading the text, I found myself asking, “Was the robot being used for the abdominal portion instead of laparoscopy or laparotomy? Was the robot used for the thoracic portion instead of thoracotomy or VATS? Was the anastomosis being done in the neck or in the chest? How was the anastomosis performed, hand sewn or stapled? Did the surgical approach include a pyloric relaxing procedure? Was a feeding tube placed at the time of esophagectomy?” Many of these technical differences have implications for OR time, pulmonary complications, etc. These variables may have an impact on measured outcomes that are independent of whether the robot was used. The answers to these questions can be found in Appendix G. I hesitate to make this suggestion given the herculean efforts involved in putting together this table, but it might be worth considering adding a few additional columns to simplify for the readers. Eg: | | | | | | | Thank you for this suggestion. We created an additional table to highlight the technical differences/surgical approaches between arms for each study. Specifically, we indicate the following when provided: the approach (McKeown, Ivor-Lewis, transhiatal), tool or technique used for the 2- or 3-stage operations (ie, robotic, thoracolaparoscopic, or open techniques for the abdomen and chest), and the anastomotic technique. Again, the main difference we were assessing was the within study comparison of the robotic portion of the operation.
| | Abdomen | Chest | Neck | Anastomosis
Study A | VAMIE | Laparoscopy | VATS | NA | EEA
| RAMIE | Laparoscopy | robotic | NA | EEA
I confess that I am often frustrated by the amount of effort that goes into general comparisons between robotic surgery and open surgery or robotic surgery and VATS/laparoscopy. The robot is a tool that is likely here to stay. With favorable ergonomics, excellent visualization, and an ever expanding pallet of graspers and energy at the surgeons disposal, adoption seems inevitable. New robotic platforms are coming to the market in the near future which are anticipated to decrease costs with new competition in the marketplace. I have argued with colleagues that a researchers time could be better spent contemplating more profound, substantive questions about the extent of resection, for example, or the intricacies of multimodal therapy, patient selection, etc. That said, I do find the authors reference to and the results of the Laparoscopic Approach to Cervical Cancer (LACC) trial intriguing. In the context of esophageal cancer, I would be surprised if we could ever detect a clear oncologic signal amidst the cacophonous noise of surgical esophagectomy research but this review, if nothing else, has prompted me to reconsider my indifference. I encourage the authors to continue with their future endeavors and would be glad to continue to participate in trial design and enrollment. | | | | | | | Thank you for your comments. We feel that an updated systematic review will be warranted when robot-assisted esophagectomy becomes widely adopted, more long term outcomes are published, and additional robotic platforms on the market.
I think that this is a very well designed and executed study of techniques for esophagectomy. The conclusions are limited due to the limitations in RCTs or other large patient population studies. The results are not surprising. Utilizing minimally invasive techniques in esophageal resection improves patent outcomes. Even when the surgical procedure is a hybrid of minimally invasive and open techniques patients do better as described in NEJM. The technique, MIS/open, versus the tool, RAMIE/VAMIE determines patient benefit. The tool (robot, LAPVATS) should be chosen based on Surgeon comfort and availability. Future studies will be impacted greatly by STS database including 5 year survival for cancer surgeries. This database is more clear in the definitions of open and MIS. Hybrid techniques will be identifiable. Hopefully this can help answer questions related to long term survival implications of open vs MIS abdominal approaches, open vs MIS chest approaches and cervical/chest anastomoses. | | | | | | | Thank you for your comments. Indeed the STS database may have additional granularity and better long-term data such that we can hopefully understand if the platform affects these outcomes. We added some of your points to our discussion.
Yes, the findings are presented in a way that is helpful for decision-making. | | | | | | | Thank you for the comment.
No recommendations; presentation format supports utilization decisions. | | | | | | | We appreciate your comments.
The report will be utilized in conjunction with the other ESP robotic-assisted surgery reports. The findings will inform policy and decisions by facilities/VISNs to purchase robotic technology. | | | | | | | Thank you for the comment.
Esophagectomy-specific outcome tracking | | | | | | | Thank you for the comment.
Recommend VA webinar/cyberseminar and presentation to the surgical community of practice to be coordinated by the National Surgery Office. | | | | | | | We are happy to participate.
I support plans for a national VHA webinar and will also assess for VISN Surgery Integrated Clinical Community presentation by ESP Center. | | | | | | | We are happy to participate.
Thoracic Surgeons, Oncologists, and GI providers | | | | | | | Anesthesiologists and surgical oncologists may be interested as well.
Very, excellent report. | | | | | | | Thank you for your comment.
Very satisfied. Report clearly assessed available literature and identified limitations/gaps and potential areas for future research. Conclusions were appropriate based upon available information and completed narrative analysis. | | | | | | | We appreciate your comments.