# APPENDIX A SEARCH STRATEGIES

## DATABASE SEARCHED & TIME PERIOD COVERED

PUBMED – 2013-2020

362 results

(Randomized) OR (“control”)) OR (randomly)) OR (trial)) OR (comparative)) OR (prospective))

AND

(Esophageal neoplasms[MESH terms]) OR (“Esophageal neoplasm”)) OR (“Esophageal cancer”)) OR (“Esophagus neoplasm”)) OR (“Oesophageal neoplasm”)) OR (“Oesophageal cancer”)) OR (“Esophageal squamous cell carcinoma”)) OR (Esophageal squamous cell carcinoma[MESH terms])) OR (Esophageal adenocarcinoma)) OR (“Esophagus cancer”)))

AND

(“minimally invasive”) OR (Minimally invasive)) OR (Laparoscopic)) OR (Thoracoscopic)) OR (Thoracolaparoscop*)) OR (Laparothoracoscop*)) OR (Video-assisted)) OR (video assisted)) OR (Video-assisted thoracic surgery)) OR (VATS)) OR (Open)) OR (Thoracotomy)) OR (Laparotomy)) OR (Transhiatal)) OR (McKeown)) OR (“Three-hole”)) OR (3-hole)) OR (Ivor-Lewis)) OR (Esophagectomy)) OR (Oesophagectomy)) OR (Esophagectomies)) OR (Oesophagectomies)) OR (Esophageal resection)) OR (Oesophageal resection)) OR (Trans-hiatal)))

AND

“thoracic surgical procedures”[MESH Terms]) OR (Robotic Surgical Procedures [MeSH terms])) OR (Robotics)) OR (Robot-assisted)) OR (Robot))

Filters: from 2013 – 2020

## DATABASE SEARCHED & TIME PERIOD COVERED

OVID MEDLINE & Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily – 2013-2020

1 result

(randomized or “control” or randomly or trial or comparative or prospective).af.

AND

exp Esophageal Neoplasms/ OR exp esophageal Squamous Cell Carcinoma/ OR (“esophageal neoplasm” or “esophageal cancer” or “esophagus neoplasm” or “oesophageal neoplasm” or “oesophageal cancer” or “esophageal squamous cell carcinoma” or “esophageal adenocarcinoma” or “esophagus cancer”).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]

AND

(“minimally invasive” or “minimally invasive” or laparoscopic or thoracoscopic or thoracolaparoscop* or laparothoracoscop* or “video-assisted” or “video assisted” or “video-assisted thoracic surgery” or “VATS” or open or thoracotomy or laparotomy or transhiatal or McKeown or “three-hole” or “3-hole” or “Ivor-Lewis” or esphagectomy or oesophagectomy or esophagectomies or oesophagectomies or “esophageal resection” or “oesophageal resection” or “trans-hiatal”).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]

AND

exp Thoracic Surgical Procedures/ OR exp/Robotic Surgical Procedures/ OR (robotics or “robot-assisted” or robot).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]

AND

Publication years 2013-2020

## DATABASE SEARCHED & TIME PERIOD COVERED

EMBASE – 2013-2020

15 results

randomized:ti,ab,kw OR control:ti,ab,kw OR randomly:ti,ab,kw OR trial:ti,ab,kw OR comparative:ti,ab,kw OR prospective:ti,ab,kw

AND

‘esophageal neoplasms’/exp OR ‘esophageal neoplasm’:ti,ab,kw OR ‘esophageal cancer’:ti,ab,kw OR ‘esophagus neoplasm’:ti,ab,kw OR ‘oesophageal neoplasm’:ti,ab,kw OR ‘oesophageal cancer’:ti,ab,kw OR ‘esophageal squamous cell carcinoma’:ti,ab,kw OR ‘esophageal squamous cell carcinoma’/exp OR ‘esophageal adenocarcinoma’:ti,ab,kw OR ‘esophagus cancer’:ti,ab,kw

AND

‘minimally invasive’:ti,ab,kw OR ‘minimally invasive’:ti,ab,kw OR laparoscopic:ti,ab,kw OR thoracoscopic:ti,ab,kw OR thoracolaparoscop*:ti,ab,kw OR laparothoracoscop*:ti,ab,kw OR ‘video-assisted’:ti,ab,kw OR ‘video assisted’:ti,ab,kw OR ‘video-assisted thoracic surgery’:ti,ab,kw OR vats:ti,ab,kw OR open:ti,ab,kw OR thoracotomy:ti,ab,kw OR laparotomy:ti,ab,kw OR transhiatal:ti,ab,kw OR mckeown:ti,ab,kw OR ‘three hole’:ti,ab,kw OR ‘3-hole’:ti,ab,kw OR ‘ivor-lewis’:ti,ab,kw OR esophagectomy:ti,ab,kw OR oesophagectomy:ti,ab,kw OR esophagectomies:ti,ab,kw OR oesophagectomies:ti,ab,kw OR ‘esophageal resection’:ti,ab,kw OR ‘oesophageal resection’:ti,ab,kw OR ‘trans-hiatal’:ti,ab,kw

AND

‘thoracic surgicial procedures’ OR ‘robotic surgerical procedures’ OR robotics:ti,ab,kw OR ‘robot-assisted’:ti,ab,kw OR robot:ti,ab,kw

AND

Publication years 2013-2020

## DATABASE SEARCHED & TIME PERIOD COVERED

COCHRANE Reviews – 2013- 2020

12 results

ID Search Hits
#1 MeSH descriptor: [Esophageal Neoplasms] explode all trees
#2 MeSH descriptor: [Esophageal Squamous Cell Carcinoma] explode all trees
#3 (Randomized OR control OR randomly OR trial OR comparative OR prospective):ti,ab,kw
#4 (“Esophageal neoplasm” OR “Esophageal cancer” OR “Esophagus neoplasm” OR “Oesophageal neoplasm” OR “Oesophageal cancer” OR “Esophageal squamous cell carcinoma” OR “Esophageal adenocarcinoma” OR “Esophagus cancer”):ti,ab,kw
#5 #1 OR #2 OR #4
#6 (“minimally invasive” OR “Minimally invasive” OR Laparoscopic OR Thoracoscopic OR Thoracolaparoscop* OR Laparothoracoscop* OR “Video-assisted” OR “video assisted” OR “Video-assisted thoracic surgery” OR VATS OR Open OR Thoracotomy OR Laparotomy OR Transhiatal OR McKeown OR “Three-hole” OR “3-hole” OR “Ivor-Lewis” OR Esophagectomy OR Oesophagectomy OR Esophagectomies OR Oesophagectomies OR “Esophageal resection” OR “Oesophageal resection” OR “Trans-hiatal”):ti,ab,kw
#7 MeSH descriptor: [Thoracic Surgical Procedures] explode all trees
#8 MeSH descriptor: [Robotic Surgical Procedures] explode all trees
#9 (robotics OR “robot-assisted” OR robot):ti,ab,kw (Word variations have been searched)
#10 #7 OR #8 OR #9
#11 #3 AND #5 AND #6 AND #10

AND

Publication years Jan 2013- Dec2020