# REFERENCES

1 United States Renal Data System. Chapter 1: Incidence, Prevalence, Patient Characteristics, and Treatment Modalities. United States Renal Data System;2018.
2 Crowley ST, Murphy K. Delivering a “New Deal” of Kidney Health Opportunities to Improve Outcomes Within the Veterans Health Administration. Am J Kidney Dis. 2018;72(3):444–450.29627134
3 National Institute of Mental Health. Major Depression. Mental Health Information: Statistics 2017; https://www.nimh.nih.gov/health/statistics/major-depression.shtml. Accessed Oct 31, 2019.
4 Palmer S, Vecchio M, Craig JC, . Prevalence of depression in chronic kidney disease: systematic review and meta-analysis of observational studies. Kidney Int. 2013;84(1):179–191.23486521
5 Xing L, Chen R, Diao Y, Qian J, You C, Jiang X. Do psychological interventions reduce depression in hemodialysis patients?: A meta-analysis of randomized controlled trials following PRISMA. Medicine. 2016;95(34):e4675.27559971
6 Farrokhi F, Abedi N, Beyene J, Kurdyak P, Jassal SV. Association between depression and mortality in patients receiving long-term dialysis: a systematic review and meta-analysis. Am J Kidney Dis. 2014;63(4):623–635.24183836
7 Weisbord SD, Mor MK, Sevick MA, . Associations of depressive symptoms and pain with dialysis adherence, health resource utilization, and mortality in patients receiving chronic hemodialysis. Clinical Journal of The American Society of Nephrology: CJASN. 2014;9(9):1594–1602.25081360
8 Kurella M, Kimmel PL, Young BS, Chertow GM. Suicide in the United States end-stage renal disease program. J Am Soc Nephrol. 2005;16(3):774–781.15659561
9 Trivedi RB, Post EP, Sun H, . Prevalence, Comorbidity, and Prognosis of Mental Health Among US Veterans. Am J Public Health. 2015;105(12):2564–2569.26474009
10 United States Renal Data System. 2017 USRDS Annual Data Report. 2017.
11 Centers for Medicare & Medicaid Services. ESRD Quality Incentive Program. 2018; https://www.cms.gov/medicare/quality-initiatives-patient-assessment-instruments/esrdqip/. Accessed April 5, 2018.
12 Shirazian S, Grant CD, Aina O, Mattana J, Khorassani F, Ricardo AC. Depression in Chronic Kidney Disease and End-Stage Renal Disease: Similarities and Differences in Diagnosis, Epidemiology, and Management. KI Reports. 2017;2(1):94–107.29318209
13 Sullivan JE, Choi NG, Vazquez CE, Neaves MA. Psychosocial Depression Interventions for Dialysis Patients, With Attention to Latinos: A Scoping Review. Research on Social Work Practice. 2019;29(8):910–923.
14 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–46.27005575
15 Wallace BC, Small K, Brodley CE, Lau J, Trikalinos TA. Deploying an interactive machine learning system in an evidence-based practice center: abstrackr. Proceedings of the 2nd ACM SIGHIT International Health Informatics Symposium (IHI). 2012:819–824.
16 Department of Veterans Affairs, Department of Defense. VA/DoD CLINICAL PRACTICE GUIDELINE FOR THE MANAGEMENT OF MAJOR DEPRESSIVE DISORDER. April 2016 2016.
17 CMS Center for Clinical Standards & Quality. Summary of Representative Clinical Depression Screening Tools. November 30, 2015 2015.
18 Furukawa TA, Reijnders M, Kishimoto S, . Translating the BDI and BDI-II into the HAMD and vice versa with equipercentile linking. Epidemiol Psychiatr Sci. 2019:1–13.
19 Stafford L, Berk M, Jackson HJ. Validity of the Hospital Anxiety and Depression Scale and Patient Health Questionnaire-9 to screen for depression in patients with coronary artery disease. Gen Hosp Psychiatry. 2007;29(5):417–424.17888808
20 Applied Health Sciences (Mental Health). Assessing the validity of the PHQ-9, HADS, BDI-II and QIDS-SR in measuring severity of depression in a UK sample of primary care patients with a diagnosis of depression. University of Aberdeen 2011.
21 Treadwell JR, Singh S, Talati R, McPheeters ML, Reston JT. A framework for best evidence approaches can improve the transparency of systematic reviews. J Clin Epidemiol. 2012;65(11):1159–1162.23017634
22 O’Connor E, Rossom RC, Henninger M, . Screening for Depression in Adults: An Updated Systematic Evidence Review for the U.S. Preventive Services Task Force. In: U.S. Preventive Services Task Force Evidence Syntheses, formerly Systematic Evidence Reviews. Rockville (MD): Agency for Healthcare Research and Quality (US); 2016.
23 U.S. Preventive Services Task Force. Appendix VII. Criteria for Assessing External Validity (Generalizability) of Individual Studies. 2017; https://www.uspreventiveservicestaskforce.org/Page/Name/appendix-vii-criteria-for-assessing-external-validity-generalizability-of-individual-studies.
24 U.S. Preventive Services Task Force. Appendix VI. Criteria for Assessing Internal Validity of Individual Studies. 2017; https://www.uspreventiveservicestaskforce.org/Page/Name/appendix-vi-criteria-for-assessing-internal-validity-of-individual-studies
25 Whiting PF, Rutjes AWS, Westwood ME, . QUADAS-2: A Revised Tool for the Quality Assessment of Diagnostic Accuracy Studies. Ann Intern Med. 2011;155(8):529–536.22007046
26 Wells GA, Shea B, O’Connell D, . The Newcastle-Ottawa Scale (NOS) for assessing the quality of nonrandomised studies in meta-analyses. http://www.ohri.ca/programs/clinical_epidemiology/oxford.asp.
27 Beck AT, Steer RA, Brown GK. BDI-II: Beck Depression Inventory Manual. Second ed. San Antonio: Psychological Corporation; 1996.
28 Lowry R. Predictive Values and Likelihood Ratios. http://vassarstats.net/clin2.html. Accessed Nov 1, 2019.
29 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. 2015;68(11):1312–1324.25721570
30 Atkins D, Chang SM, Gartlehner G, . Assessing applicability when comparing medical interventions: AHRQ and the Effective Health Care Program. J Clin Epidemiol. 2011;64(11):1198–1207.21463926
31 Kimmel PL, Weihs K, Peterson RA. Survival in hemodialysis patients: the role of depression. J Am Soc Nephrol. 1993;4(1):12–27.8400064
32 The Center for Innovative Public Health Research. CESD-R: The Center for Epidemiologic Studies Depression Scale Revised. https://cesd-r.com/about-cesdr/. Accessed Nov 1, 2019.
33 Hedayati SS, Bosworth HB, Kuchibhatla M, Kimmel PL, Szczech LA. The predictive value of self-report scales compared with physician diagnosis of depression in hemodialysis patients. Kidney Int. 2006;69(9):1662–1668.16598203
34 Snaith RP, Zigmond AS. The hospital anxiety and depression scale. Br Med J (Clin Res Ed). 1986;292(6516):344.
35 Loosman WL, Siegert CE, Korzec A, Honig A. Validity of the Hospital Anxiety and Depression Scale and the Beck Depression Inventory for use in end-stage renal disease patients. Br J Clin Psychol. 2010;49(Pt 4):507–516.20021730
36 Preljevic VT, Osthus TB, Sandvik L, . Screening for anxiety and depression in dialysis patients: comparison of the Hospital Anxiety and Depression Scale and the Beck Depression Inventory. J Psychosom Res. 2012;73(2):139–144.22789418
37 Sheikh JI, Yesavage JA. Geriatric Depression Scale (GDS): Recent evidence and development of a shorter version. Clinical Gerontology. 1986;5:165–173.
38 Yesavage JA, Brink TL, Rose TL, . Development and validation of a geriatric depression screening scale: A preliminary report. J Psychiatr Res. 1982;17(1):37–49.7183759
39 Balogun RA, Turgut F, Balogun SA, Holroyd S, Abdel-Rahman EM. Screening for depression in elderly hemodialysis patients. Nephron. 2011;118(2):c72–77.21150214
40 Giordano M, Tirelli P, Ciarambino T, . Screening of depressive symptoms in young-old hemodialysis patients: relationship between Beck Depression Inventory and 15-item Geriatric Depression Scale. Nephron. 2007;106(4):c187–192.17596728
41 Hamilton M. Development of a rating scale for primary depressive illness. Br J Soc Clin Psychol. 1967;6(4):278–296.6080235
42 Gencoz F, Gencoz T, Soykan A. Psychometric properties of the Hamilton Depression Rating Scale and other physician-rated psychiatric scales for the assessment of depression in ESRD patients undergoing hemodialysis in Turkey. Psychology Health & Medicine. 2007;12(4):450–459.
43 Kroenke K, Spitzer RL, Williams JB. The PHQ-9: validity of a brief depression severity measure. J Gen Intern Med. 2001;16(9):606–613.11556941
44 Watnick S, Wang PL, Demadura T, Ganzini L. Validation of 2 depression screening tools in dialysis patients. Am J Kidney Dis. 2005;46(5):919–924.16253733
45 Wang YY, Zhang WW, Feng L, . Development and Preliminary Validation of a Depression Assessment Tool for Maintenance Hemodialysis Patients. Therapeutic Apheresis & Dialysis: Official Peer-Reviewed Journal of the International Society for Apheresis, the Japanese Society for Apheresis, the Japanese Society for Dialysis Therapy. 2019;23(1):49–58.
46 Neitzer A, Sun S, Doss S, Moran J, Schiller B. Beck Depression Inventory-Fast Screen (BDI-FS): an efficient tool for depression screening in patients with end-stage renal disease. Hemodialysis International. 2012;16(2):207–213.22754932
47 Troidle L, Wuerth D, Finkelstein S, Kliger A, Finkelstein F. The BDI and the SF36: which tool to use to screen for depression? Adv Perit Dial. 2003;19:159–162.14763054
48 Bautovich A, Katz I, Loo CK, Harvey SB. Beck Depression Inventory as a screening tool for depression in chronic haemodialysis patients. Australasian Psychiatry. 2018;26(3):281–284.29457471
49 Collister D, Rodrigues JC, Mazzetti A, . Single Questions for the Screening of Anxiety and Depression in Hemodialysis. Canadian Journal of Kidney Health & Disease. 2019;6:2054358118825441.30719321
50 Grant D, Almond MK, Newnham A, Roberts P, Hutchings A. The Beck Depression Inventory requires modification in scoring before use in a haemodialysis population in the UK. Nephron. 2008;110(1):c33–38.18689985
51 van den Beukel TO, Siegert CE, van Dijk S, Ter Wee PM, Dekker FW, Honig A. Comparison of the SF-36 Five-item Mental Health Inventory and Beck Depression Inventory for the screening of depressive symptoms in chronic dialysis patients. Nephrology Dialysis Transplantation. 2012;27(12):4453–4457.
52 Alsuwaida A, Alwahhabi F. The diagnostic utility of Self-Reporting Questionnaire (SRQ) as a screening tool for major depression in hemodialysis patients. Saudi J Kidney Dis Transpl. 2006;17(4):503–510.17186684
53 Chilcot J, Wellsted D, Farrington K. Screening for depression while patients dialyse: an evaluation. Nephrology Dialysis Transplantation. 2008;23(8):2653–2659.
54 First M. User’s guide for the Structured clinical interview for DSM-IV axis I disorders SCID-I : Clinician version. Washington, DC: American Psychiatric Press; 1997.
55 Sheehan DV, Lecrubier Y, Sheehan KH, . The Mini-International Neuropsychiatric Interview (M.I.N.I.): the development and validation of a structured diagnostic psychiatric interview for DSM-IV and ICD-10. J Clin Psychiatry. 1998;59: Suppl 20:22–33;quiz 34-57.
56 Hedayati. Accuracy of depression evaluation in hemodialysis patients. Nature Clinical Practice Nephrology. 2006;2(8):409–410.
57 Sacks CR, Peterson RA, Kimmel PL. Perception of Illness and Depression in Chronic Renal Disease. Am J Kidney Dis. 1990;15(1):31–39.2294731
58 World Health Organization. A User’s Guide to the Self Reporting Questionnaire (SRQ). Geneva: Division of Mental Health World Health Organization,;1994.
59 Beck AT, Steer RA, Brown GK. BDI - FastScreen for Medical Patients. https://www.pearsonassessments.com/store/usassessments/en/Store/Professional-Assessments/Personality-%26-Biopsychosocial/Brief/BDI---FastScreen-for-Medical-Patients/p/100000173.html?tab=product-details.
60 Blumenfield M, Levy NB, Spinowitz B, . Fluoxetine in depressed patients on dialysis. Int J Psychiatry Med. 1997;27(1):71–80.9565715
61 Friedli K, Guirguis A, Almond M, . Sertraline Versus Placebo in Patients with Major Depressive Disorder Undergoing Hemodialysis: A Randomized, Controlled Feasibility Trial. Clinical Journal of The American Society of Nephrology: CJASN. 2017;12(2):280–286.28126706
62 Taraz M, Khatami MR, Dashti-Khavidaki S, . Sertraline decreases serum level of interleukin-6 (IL-6) in hemodialysis patients with depression: results of a randomized double-blind, placebo-controlled clinical trial. Int Immunopharmacol. 2013;17(3):917–923.24121064
63 Mehrotra R, Cukor D, Unruh M, . Comparative Efficacy of Therapies for Treatment of Depression for Patients Undergoing Maintenance Hemodialysis: A Randomized Clinical Trial. Ann Intern Med. 2019;26:26.
64 Hosseini SH, Espahbodi F, Mirzadeh Goudarzi SM. Citalopram versus psychological training for depression and anxiety symptoms in hemodialysis patients. Iran J Kidney Dis. 2012;6(6):446–451.23146983
65 Wang Y, Liu Y, Lian Y, Li N, Liu H, Li G. Efficacy of High-Dose Supplementation With Oral Vitamin D3 on Depressive Symptoms in Dialysis Patients With Vitamin D3 Insufficiency: A Prospective, Randomized, Double-Blind Study. J Clin Psychopharmacol. 2016;36(3):229–235.27022679
66 Gharekhani A, Khatami MR, Dashti-Khavidaki S, . The effect of omega-3 fatty acids on depressive symptoms and inflammatory markers in maintenance hemodialysis patients: a randomized, placebo-controlled clinical trial. Eur J Clin Pharmacol. 2014;70(6):655–665.24643636
67 Duarte PS, Miyazaki MC, Blay SL, Sesso R. Cognitive-behavioral group therapy is an effective treatment for major depression in hemodialysis patients. Kidney Int. 2009;76(4):414–421.19455196
68 Al Saraireh FA, Aloush SM, Al Azzam M, Al Bashtawy M. The Effectiveness of Cognitive Behavioral Therapy versus Psychoeducation in the Management of Depression among Patients Undergoing Haemodialysis. Issues Ment Health Nurs. 2018;39(6):514–518.29370555
69 Cukor D, Ver Halen N, Asher DR, . Psychosocial intervention improves depression, quality of life, and fluid adherence in hemodialysis. J Am Soc Nephrol. 2014;25(1):196–206.24115478
70 Lerma A, Perez-Grovas H, Bermudez L, Peralta-Pedrero ML, Robles-Garcia R, Lerma C. Brief cognitive behavioural intervention for depression and anxiety symptoms improves quality of life in chronic haemodialysis patients. Psychology & Psychotherapy: Theory, Research & Practice. 2017;90(1):105–123.
71 Kalani L, Aghababaeian H, Majidipour N, . The effects of acupressure on severity of depression in hemodialysis patients: a randomized controlled trial. Journal of Advanced Pharmacy Education & Research. 2019;9(S2):67–72.
72 Tsay SL, Cho YC, Chen ML. Acupressure and Transcutaneous Electrical Acupoint Stimulation in improving fatigue, sleep quality and depression in hemodialysis patients. Am J Chin Med. 2004;32(3):407–416.15344424
73 Heshmatifar N SHMASNMRRMH. The effect of benson relaxation technique on depression in patients undergoing hemodialysis. Journal of babol university of medical sciences. 2015;17(8):34.
74 Kouidi E, Karagiannis V, Grekas D, . Depression, heart rate variability, and exercise training in dialysis patients. Eur J Cardiovasc Prev Rehabil. 2010;17(2):160–167.19745744
75 Beizaee Y, Rejeh N, Heravi-Karimooi M, Tadrisi SD, Griffiths P, Vaismoradi M. The effect of guided imagery on anxiety, depression and vital signs in patients on hemodialysis. Complement Ther Clin Pract. 2018;33:184–190.30396619
76 Rahimipour M, Shahgholian N, Yazdani M. Effect of hope therapy on depression, anxiety, and stress among the patients undergoing hemodialysis. Iran J Nurs Midwifery Res. 2015;20(6):694–699.26793255
77 Widyaningrum, Siswanto A, Djarwoto B. Effects of Latihan Pasrah Diri in Quality Of Life in Chronic Kidney Disease-Dialysis Patients with Depression Symptoms. Acta Interna - The Journal of Internal Medicine. 2013;3(2):16–22.
78 Thomas Z, Novak M, Platas SGT, . Brief Mindfulness Meditation for Depression and Anxiety Symptoms in Patients Undergoing Hemodialysis: A Pilot Feasibility Study. Clinical Journal of The American Society of Nephrology: CJASN. 2017;12(12):2008–2015.29025788
79 Babamohamadi H, Sotodehasl N, Koenig HG, Al Zaben F, Jahani C, Ghorbani R. The Effect of Holy Qur’an Recitation on Depressive Symptoms in Hemodialysis Patients: A Randomized Clinical Trial. Journal of Religion & Health. 2017;56(1):345–354.27393704
80 American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. Fifth ed. Arlington, VA: American Psychiatric Association; 2013.
81 Palmer SC, Natale P, Ruospo M, . Antidepressants for treating depression in adults with end-stage kidney disease treated with dialysis. Cochrane Database of Systematic Reviews. 2016(5):CD004541.