# DISCUSSION

We identified 16 studies evaluating the diagnostic accuracy of a variety of depression screening tools, and 20 RCTs examining the effectiveness of pharmacological and non-pharmacological interventions for adults with ESRD and depression. Overall, samples included in studies evaluating screening tools bear little resemblance to Veterans seeking care in VHA settings. In addition, except for the BDI-II, the evidence base is quite limited due to the small number of studies examining each tool and small samples. Similarly, for intervention studies, we identified limited research for each intervention, sample sizes were small, and nearly all studies were hampered by methodological flaws.

The BDI-II was by far the best-studied screening tool. However, there was heterogeneity in the way depression was operationalized. Half of the studies evaluated the performance characteristics associated with thresholds intended to screen for MDD, while the other half defined depression more loosely, with some including subclinical depressive symptoms. Among the studies evaluating the BDI-II as a tool to identify MDD, the threshold that best optimized the balance between sensitivity and specificity for patients with ESRD was ≥16. Interestingly, this finding was reported in the single study that screened for MDD specifically and included a VHA population. Of note, the PHQ-9 tool is commonly used in VHA primary care settings, but we identified only a single, 15-year-old study evaluating it in this patient population.^44^

Table 11 uses data from the 2 US^39,44^ and 2 UK studies^50,53^ that screened specifically for MDD to compare positive and negative predictive values across reported MDD prevalence rates for a) the general US population (7.1%)^3^; b) Veterans receiving care in VHA patient-centered medical homes (Patient Aligned Care Teams [PACT]; 13.5%)^9^; c) patients with ESRD, diagnosed using a gold standard clinical interview (22.8%)^4^; d) Veterans with ESRD (method of diagnosis NR; 33%)^10^; and e) patients with ESRD, diagnosed using a screening tool (39.3%).^4^ Although these rates are representative of US populations, we included the 2 UK studies because the population and health system is similar to the VHA. Studies evaluate both the BDI-II and the PHQ-9 and highlight the impact of the population specific prevalence rate on positive and negative predictive values for a specific threshold. Across studies, the negative predictive values, or accuracy of eliminating depression as a diagnosis are generally high, and false negative findings are unlikely. However, the positive predictive values, or accuracy of correctly diagnosing depression, range from 0.26 to 0.88, and depending on the population, potential of a false positive may be high. Providers should keep this in mind if using the results of depression screening tools to guide treatment decisions.

Across the 4 BDI-II studies, a cutoff of ≥16 provides the best balance between sensitivity and specificity. In fact, we found that in some studies, the BDI-II performed reasonably well when compared to a gold standard clinical interview. The caveat however, is that there was heterogeneity across studies in the way the tools were administered, and very few studies contributed data for the same thresholds. Most of the diagnostic accuracy studies were conducted outside of the US, and/or in health systems that differ from the VHA. Studies of non-Veterans with ESRD may also be less applicable due to both demographic (eg, gender, socioeconomic and housing status) and clinical differences (eg, multiple comorbidities, substance use, mental health).

Table 11 Positive and negative predictive values associated with depression rates in 4 US populations

Author, Year N, % MDD (Ref), % MDD Tool, Cutoff | Sensitivity (%) | Specificity (%) | Prevalence Assumption (%) | Positive Predictive Value | Negative Predictive Value
Beck Depression Inventory-II (BDI-II)
Balogun, 2011^39^; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 7.1^a^ | 0.88 | 0.50
Balogun, 2011^39^; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 13.5^b^ | 0.32 | 0.94
Balogun, 2011^39^; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 22.8^c^ | 0.47 | 0.89
Balogun, 2011^39^; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 33.0^d^ | 0.59 | 0.83
Balogun, 2011^39^; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 39.3^e^ | 0.66 | 0.79
Watnick, 2005^44^; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 7.1^a^ | 0.33 | 0.99
Watnick, 2005^44^; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 13.5^b^ | 0.50 | 0.98
Watnick, 2005^44^; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 22.8^c^ | 0.66 | 0.97
Watnick, 2005^44^; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 33.0^d^ | 0.76 | 0.95
Watnick, 2005^44^; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 39.3^e^ | 0.81 | 0.94
Chilcot, 2008^53^; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 7.1^a^ | 0.35 | 0.99
Chilcot, 2008^53^; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 13.5^b^ | 0.52 | 0.98
Chilcot, 2008^53^; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 22.8^c^ | 0.67 | 0.96
Chilcot, 2008^53^; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 33.0^d^ | 0.77 | 0.94
Chilcot, 2008^53^; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 39.3^e^ | 0.82 | 0.92
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 7.1^a^ | 0.26 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 13.5^b^ | 0.42 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 22.8^c^ | 0.57 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 33.0^d^ | 0.69 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 39.3^e^ | 0.74 | 1.0
Patient Health Questionnaire 9 (PHQ-9)
Watnick, 2005^44^; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 7.1^a^ | 0.47 | 0.99
Watnick, 2005^44^; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 13.5^b^ | 0.64 | 0.99
Watnick, 2005^44^; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 22.8^c^ | 0.77 | 0.97
Watnick, 2005^44^; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 33.0^d^ | 0.85 | 0.96
Watnick, 2005^44^; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 39.3^e^ | 0.88 | 0.95

a General US population,

b Veterans receiving care in VHA patient-centered medical homes,

c Patients with ESRD, diagnosed using a gold standard clinical interview,

d Veterans with ESRD (diagnosis method NR),

e Patients with ESRD, diagnosed using a screening tool.

Abbreviations: BDI-II = Beck Depression Inventory-II; MDD = Major Depressive Disorder

Studies evaluating a (typically short) screening tool against an established validated tool performed well overall. Since the QIP requires a follow-up assessment after an initial positive screen, these short tools may be good options for this purpose. In particular, the BDI-FS performed well when compared to the BDI-II.

We identified no studies examining the impact of screening on intermediate or health outcomes. Only 1 study examined subgroup differences in screening, and it found that non-depressed participants reported significantly more somatic symptoms when depression screening was administered during dialysis sessions versus off dialysis. Not only were scores on somatic items significantly higher, but BDI-II scores were significantly higher as well. This has implications for dialysis units working to streamline processes, as it illustrates the potential for over-diagnosis and over-treatment.

SSRIs, compared either to placebo or an active comparator, were the best-studied pharmacological intervention. Findings from placebo-controlled trials were mixed, and the evidence is insufficient due to lack of consistent findings, small samples, and other methodologic flaws. We found low-strength evidence that despite improvement in both treatment groups, there is no difference between sertraline and CBT. We found moderate-strength evidence that high dose vitamin D3 is ineffective for reducing depressive symptoms. Vitamin D3 is an interesting intervention for patients with ESRD, due to the risk of hyperphosphatemia in this population, which can be exacerbated by vitamin D. Five patients withdrew from the study due to treatment-related AEs. Though not attributed to hyperphosphatemia, the reported AEs (ie, joint pain, diarrhea, nausea and vomiting) may be related.

Across non-pharmacological interventions, we found low-strength evidence that CBT is more effective than psychotherapy or placebo for reducing depression severity and increasing quality of life. We also found low-strength evidence that acupressure is more effective for reducing depression severity than sham or usual care. Findings for all other non-pharmacological interventions were insufficient to draw conclusions.

Table 12 Strength of evidence of intervention effectiveness

Intervention | N | Depression Severity | Quality of Life | Fatigue | Sleep Quality
SSRI vs control | 94 | Insufficient | -- | -- | --
Citalopram vs psychological training | 44 | Insufficient | -- | -- | --
Sertraline vs CBT | 120 | No Difference | -- | -- | --
CBT vs psychotherapy | 90 | Benefit | Benefit | -- | --
CBT vs psychoeducation | 130 | Insufficient | -- | -- | --
CBT vs control | 125 | Benefit | Benefit | -- | --
MBSR vs TAU | 41 | Insufficient | -- | -- | --
Guided Imagery vs control | 80 | Insufficient | -- | -- | --
Benson Relaxation Technique vs. control | 70 | Insufficient | -- | -- | --
Latihan Pasrah Diri vs control | 36 | Insufficient | Insufficient | -- | --
Hope Therapy vs active control | 50 | Insufficient | -- | -- | --
Quran vs TAU | 60 | Insufficient | -- | -- | --
Exercise training vs. control | 50 | Insufficient | -- | -- | --
Acupressure vs TAU | 204 | Benefit | -- | Insufficient | Insufficient
Acupressure vs sham | 96 | Benefit | -- | -- | --
Acupressure vs TEAS | 108 | Insufficient | -- | Insufficient | Insufficient
High dose Vitamin C vs placebo | 746 | No Difference | -- | -- | --
Omega 3 Fatty Acids vs placebo | 54 | Insufficient | -- | -- | --

Note. Colors represent the Strength of Evidence (SOE). Gray = Insufficient, yellow = low SOE, blue = moderate SOE.

Abbreviations: CBT = cognitive behavioral therapy, MBSR = mindfulness-based stress reduction, SSRI = selective serotonin reuptake inhibitor, TAU = treatment as usual.

Very few intervention studies reported harms; however, most interventions presented minimal risk. Harms related to SSRIs were not uniformly reported. That said, the type and rate of harms reported and or evaluated in multiple studies suggest little to no increase in risk compared to otherwise healthy individuals using SSRIs.

Differences by subpopulation were reported in very few studies, and no reported differences were insufficient to form conclusions.

## LIMITATIONS

There are several important limitations to this evidence base, in addition to small samples sizes and a limited number of studies examining specific tool thresholds and specific interventions. Across studies of both screening and treatment, a good number of studies were conducted outside of the United States, many of which examined participants and health systems that differ from general US and Veteran populations. In addition, the lack of methodological detail reported in many of the studies resulted in poor quality ratings, and uncertainty about study processes. For screening studies, the definition of depression varied widely, which hampered our ability to synthesize the body of research for each tool. Future studies should use standardized language (eg, DSM-5^80^).

For intervention studies, there was significant heterogeneity in outcome measures used to assess depressive symptoms, and it is possible that the small sample sizes in many of the studies resulted in a lack of power to detect differences.

This is the only systematic review to date that examines the breadth of both screening and treatment of depression in adults with ESRD. This review confirms and adds to a 2016 Cochrane review of antidepressants in adults with ESRD that included meta-analyses of harms reported in trials included in our report.^81^ Although we also included more recent trials, outcomes were not reported in a way that allowed for a quantitative synthesis of harms. Newer trials included in our review, particularly the ASCEND (A Trial of Sertraline vs. Cognitive Behavioral Therapy for End-stage Renal Disease Patients with Depression) trial,^63^ add to both the pharmacological and non-pharmacological evidence.

## RESEARCH GAPS/FUTURE RESEARCH

There are many areas ripe for further research in this field. As described above, diagnostic accuracy studies of depression tools conducted in US and Veteran ESRD populations are needed. In addition, the PHQ-9 is a commonly used tool in VHA and community settings. Additional research evaluating its performance characteristics is warranted. There are a handful of studies supporting the use of the BDI-II as a screening tool for MDD in this population. Larger studies with representative samples evaluating a range of thresholds would help to guide decision-making and implementation. Relatedly, there were several high-performing tools that used the BDI-II as a reference standard. Short, population-targeted tools (eg, BDI-FS, GDS-15) may be appropriate as an initial screen for depression in dialysis settings. However, more research is needed to validate existing findings. Finally, the DI-MHD was the only screening tool we identified developed specifically for this population. It performed well as compared to the BDI in a large sample in China; however, to date it has not been compared to a gold standard clinical interview. Additional research validating the DI-MHD has the potential to impact screening practices in this population.

We identified no studies examining the impact of screening on outcomes, and only 1 study that examined subgroup differences. This study compared differences in overall and somatic BDI-II scores when completed on versus off dialysis and touches on only 1 of many important implementation issues (eg, timing, location, administration). Also important but missing is evidence of potential demographic and clinical differences. Research in these areas will help decisionmakers to implement screening processes that are not only evidence-based, but also the best fit for their patient population.

Future research is also needed to better evaluate both pharmacological and non-pharmacological interventions for this population.

## IMPLICATIONS FOR THE VHA

Our findings have several implications for the VHA. They will be used to help guide the selection and implementation of screening for Veterans with ESRD, and the interventions for those with comorbid depressive disorders. They will also help to guide future Health Services Research and Development (HSR&D) priorities. Currently in VHA settings, Veterans with ESRD are screened for depression using a variety of tools, including the PHQ-9. Our findings highlight the moderate positive predictive values in this population. Clinicians should be prepared to validate positive screens prior to making treatment decisions that may be burdensome or introduce the possibility of harm.

## CONCLUSION

There is limited research evaluating the diagnostic accuracy of most screening tools for depression in patients with ESRD, and the existing studies may not be generalizable to patients in the US, or Veterans receiving care in VHA settings. Screening and intervention studies suffer from limitations related to methodological quality or reporting. In adults with ESRD, the BDI-II with a cutoff of ≥16 provides a good balance of sensitivity and specificity. More research is needed to support the use of other tools. We found low-strength evidence that sertraline and CBT provide benefit for depressive symptoms. There is low-strength evidence that CBT is more effective than psychotherapy or placebo for depressive symptoms and quality of life, low-strength evidence that acupressure is more effective for reducing depression than sham or usual care, and moderate-strength evidence that high-dose vitamin D3 is ineffective. Although our ability to form conclusions about the effectiveness of interventions for depression in patients with ESRD is limited, it is important to note that across studies within group improvements were common, despite insignificant differences between groups, suggesting that treatment generally may be better than no treatment in this population. More research is needed.