# RESULTS

We reviewed a total of 7,452 studies. After title and abstract review, 149 met inclusion criteria. Upon full-text review, we included a total of 20 RCTs and 16 diagnostic accuracy studies. RCTs examined in Key Questions 4 and 6 were also included in Key Question 3, and the single study included for Key Question 5 was also included in Key Question 1 (see Figure 2; quality assessment is presented in Appendices C and D).

Figure 2 Literature Flow Chart

*after deduplication

Note: studies in KQs 4 & 6 are also included in the KQ3 total, and the KQ5 study is included in KQ1 total

## KEY QUESTION 1 What are the performance characteristics of screening tools for depression in patients with ESRD?

Sixteen studies examined the performance characteristics for depression screening in patients with ESRD. Nine studies examined the performance of the Beck Depression Inventory-II (BDI-II).^27^ Other tools include the Cognitive Depression Index (CDI^31^; 4 studies), the Center for Epidemiologic Studies – Depression Scale (CES-D^32^; 1 study^33^), the Hospital Anxiety and Depression Scale - Depressive Subscale (HADS-D^34^; 2 studies^35,36^), the Geriatric Depression Scale-15 (GDS-15^37,38^; 2 studies^39,40^), the Hamilton Depression Rating Scale (Ham-D^41^; 1 study^42^), the Patient Health Questionnaire 9 (PHQ-9^43^; 1 study^44^), and others. Of note, we identified only 1 development and validation study of a depression screening tool targeting patients on maintenance dialysis (Depression Inventory – Maintenance Hemodialysis [DI-MHD]).^45^ Table 2 provides study characteristics.

Five studies^33,39,44,46,47^ were of US populations, with 2 studies including participants at Veterans Health Administration (VHA) facilities.^33,44^ Other studies were located in Australia,^48^ Canada,^49^ China,^45^ Italy,^40^ the Netherlands,^50,51^ Norway,^36^ Saudi Arabia,^52^ Turkey,^42^ and the United Kingdom (UK; see Table 2).^50,53^

Most studies included only patients undergoing hemodialysis (HD). Only 4 studies also included participants undergoing peritoneal dialysis (PD).^35,36,44,47^ Across studies reporting time on dialysis, the minimum number of (mean) months was 8.5^36^ and the maximum was 72.2 (see Table 2).^42^

Of the 16, 11 studies compared screening tools (index test) to a gold standard clinical interview (eg, Structured Clinical Interview for DSM-IV [SCID-I]^54^, Mini-International Neuropsychiatric Interview [MINI]^55^), and 5 compared tools to other established, validated assessment measures (eg, Beck Depression Inventory [BDI-II]^27^, Hospital Anxiety and Depression Scale [HADS]^34^). One study compared the BDI-II to a clinical interview, and another tool to the BDI-II.^45^ For the purpose of this review, we focus primarily on the studies using a clinical interview as a reference standard, and summarize the findings of those comparing screening tools to other established tools.

Only 5 studies screened participants for MDD specifically.^39,44,46,48,52,53^ Nine studies screened for less severe depressive disorders (eg, dysthymia, pervasive depressive disorder) and/or subclinical depressive symptoms in addition to MDD,^35,36,40,42,45,47,49,51,56^ and 1 study examined performance characteristics and thresholds for both MDD and less severe depression (see Table 2).^50^

The 16 studies were relatively similar in quality, with the risk of bias largely unclear for patient selection, the index test, and the reference standard. For patient selection, unclear ratings were primarily due to the lack of detail related to the sequence of sample enrollment. For the index test, few studies reported whether study staff were trained in administration or interpretation of the test, and for the reference standard, very few studies reported information related to fidelity. Risk of bias ratings for timing and flow were low for all but 3 studies, with 1 unclear ROB,^52^ and 2 high ROB (see Figure 3 and Appendix C for more detail).^39,40^

Figure 3 Risk of Bias of Diagnostic Accuracy Studies

Note. See Appendix C for a description of categories and item list.

Table 2 Characteristics of studies examining the diagnostic accuracy of depression screening tools in patients with ESRD (KQ1)

Author, Year N enrolled Country/US region, years of enrollment | Study setting Sample characteristics and demographics | Inclusion Criteria/Exclusion Criteria | Index Test(s); Administration | Reference Standard; Administration | % MDD Positive per Index Test; Reference Standard
Alsuwaida, 2006^52^; N = 26; Saudi Arabia | Single Site: hospital-based outpatient HD unit; 42% Female; Age: 48.1(15.1); Education: NR; HD: 100%; Dialysis duration: NR; History of depression: NR | Inclusion: 18+ years of age, ESRD and on maintenance HD for 3+ months; Exclusion: Inability to participate in psychiatric interview, acute kidney failure, and delirium. Diagnosed with psychiatric disorders other than MDD | [underlined: SRQ (Arabic Version):] Self-report. Timing: within a week of clinical interview | [underlined: Clinical Interview:] All participants interviewed by the same psychiatrist (blinded to index test). Timing: up to a week before the index test. | SRQ=NR; 15.4%
Balogun, 2011^39^; N = 96; US | Multisite: dialysis units; Of 89 participants:; 56% Female; Age: 73.5(6.2); White: 56.2%; Black: 43.8%; Education: NR; HD: NR; Dialysis duration: NR; History of depression: NR | Inclusion: 65+ with ESRD treated with chronic hemodialysis and able to give their informed consent; Exclusion: acute or other chronic illness [ie, metabolic (organic) brain syndrome, known malignancy, dementia], currently using antidepressants, and active alcohol or recreational drug abuse, did not speak English | [underlined: BDI, GDS-15:] NR | [underlined: Clinical Interview:] Geriatric Psychiatrist | Of 62: BDI≥10= 37.1%, GDS-15 ≥5 = 32.3%; 30.6%
Bautovich, 2018^48^; N = 45; Sydney, Australia | Single site: outpatient dialysis unit; 42% Female; Age: primarily 65+; Education: NR; HD: 100%; Days on dialysis: M= 1241(1098); History of depression: NR | Included: 18+ years of age, receiving HD, adequate English language skills; Excluded: evidence of psychosis, drug or alcohol dependence, or cognitive dysfunction | [underlined: BDI, CDI:] Self-report. Timing: before clinical interview. | [underlined: Clinical Interview:] Interviewed by a senior psychiatry registrar or psychiatrist, both of whom were experienced in diagnosing depression amongst those with chronic medical illness; Timing: completed immediately after index tests | BDI, CDI = NR; 13.3%
Chilcot, 2008^53^; N = 40; UK | Multisite: outpatient renal service; 40% Female; Age: 53.2(14.2); White: 87.5%; Black Caribbean: 10%; Asian: 2.5%; Education: NRHD: 100% (high-flux or on-line) 3x/week Months on dialysis; M=51.2; History of depression: NR | Included: Adult ESRD receiving HD for >3 months.; Excluded: Psychiatric illnesses other than MDD, <23 MMSE | [underlined: BDI, CDI:] Self-report. Completed on and off dialysis. On-dialysis commenced 30 minutes after the start of a stable session. Off-dialysis conducted at the same as the MINI, M=10.7(4.2) days before/after. | [underlined: MINI (ref for BDI):] Administration by a research psychologist who was trained by a consultant psychiatrist. Timing: 10.7(4.2) days before/after the on-dialysis BDI, and on the same day as the off-dialysis BDI.; [underlined: BDI-II (ref for CDI):] Self-report. Same day as the CDI. | BDI≥16 on dialysis = 32.5%, off dialysis = 30%, CDI≥10 on and off dialysis = 32.5%; 22.5%
^1^Collister, 2019^49^; N = 50; Canada | Multisite: outpatient HD units; 48% Female; Age: 64(12.4); Education: NR; HD: 100%; 3+x/week: 96%; Hours of HD M= 3.6(0.4); Dialysis duration: NR; History of depression: NR; Antidepressants: 16% | Included: 18+ years of age, receiving in-center hemodialysis ≥2x weekly for at least the last 90 days; Excluded: unable to complete the study instruments due to a cognitive impairment or an English language barrier | [underlined: Single question from the ESAS:] Self-report scale (0-10) re: feeling blue or sad. Timing: taken during dialysis during the same session as the reference test. | [underlined: HADS:] Self-report. Timing: taken during dialysis during the same session as the reference test. | ESAS = NR; HADS≥7=54%
^1^Gencoz, 2007^42^; N = 45; Turkey | Single site: hospital-based outpatient HD unit; 42.2% Female; Age: 41.64(11.7); ≤ Middle school: 37.9%; HD: 100%; Months on HD M=72.24(48.48); History of depression: NR | Included: medically stable with no hospital admission for any reason within the last 3 months, and maintained on dialysis for at least 12 months; Excluded: presence of cognitive impairment indicated by MMSE score lower than 24, presence of a history of a psychiatric diagnosis or treatment in the last 6 months, and presence of some practical difficulties like probability of moving to another city, blindness or low educational level, which may decrease the patients’ ability to comprehend and/or follow the study protocol. Patients who did not complete all baseline assessments were also excluded from the study. | [underlined: Ham-D:] Administered at baseline and the following month by a clinical psychologist that was blind to the reference standard. Timing re: reference standard: NR | [underlined: SCID-I (Turkish Translation):] Administered at baseline and the following month by a clinical psychologist that was blind to the reference standard. Timing re: index test: NR | Ham-D NR; 4% MDD, 18% other depressive disorders
^1^Giordano, 2007^40^; N = 31; Italy | Single site: hospital-based HD unit; 35.5% Female; Age: 70.3(1); Race: NR; Education: NR; HD: 100%; Dialysis duration: NR; History of depression: NR | Inclusion: 3+ HD/wk, 65+ years old, maintaining functional independence or loss of it in only 1 of the 6 basic ADL, no evidence of significant cognitive impairment per MMSE >24, no evidence of severe diseases that might highly influence mood state (eg, cancer, symptomatic cerebrovascular disease with residual deficit, schizophrenia and other psychoses), and disease severity as evaluated by the CIRS for overall illness severity for which >3 is moderate; Exclusion: Taking antidepressants | [underlined: GDS-15:] Self-report. Administered by a trained interviewer. Timing: same session as reference standard. | [underlined: BDI:] Self-report. Administered by a trained interviewer. Timing: same session as index test. | GDS-15 ≥6 = 32%; BDI-II ≥14=29%
^2^Grant, 2008^50^; N = 57; UK | Single site: outpatient HD unit; 29.8% Female; Age: 62.5(15.8); Non-White 7%; Education: NR; HD: 100%; Dialysis duration: NR; History of depression: NR | Included: 18 and 90 years of age, ESRD for 3+ months, receiving HD 3x/week.; Excluded: Current psychiatric care, on medication for a psychiatric illness or had seen a psychiatrist for follow-up within the last 2 years, severe co-morbid illness requiring hospitalization. | [underlined: BDI:] Self-report. Distributed by a healthcare assistant during a HD session. | [underlined: Clinical Interview (based on ICD-10 diagnosis):] Interviewed by a trained psychologist. Included a full psychiatric history and MMSE. Timing: within 1 week of index test | BDI-II ≥10 = 56.1%; 12.3%; BDI-II ≥15 = 31.6%;
^1^Hedayati, 2006^56^; N = 98; US; Durham, NC; March 2003-April 2004 | Multi-site: outpatient dialysis units (VA, 2 non-VA); 44.9% Female; Age: 57.2(13.8); Veterans: 26.5%; AA/Black: 80.6%; White: 14.3%; Other: 5.1%; ≤High school: ≈ 44.5%; HD: 100%; Years on dialysis: M=4.1(3.8); History of depression: NR | Included: English-speaking with health-care power of attorney and could sign consent.; Excluded: NR | [underlined: BDI, CDI, CESD, Feinstein Scale;] RA administered BDI/CESD/Feinstein Scale at enrollment. | [underlined: SCID-I:] Administered by a nephrologist. Timing: within 1 week of index tests | BDI≥14 = 30.6%, CESD ≥18 = 30.6%; 26.5%; 17.3% MDD
^1^Loosman, 2010^35^; N = 62; Amsterdam; Feb-June 2008 | Single site: hospital-based HD and outpatient PD; 46.8% Female; Age: 63.5(14.9); 64.5% Dutch ethnicity; Education: NR; HD: 82%; PD 18%; Months on dialysis: 46(65); Previous depression: 9.7%; Antidepressants: 3.2% | Included: Patients with ESRD treated with HD or PD; Excluded: Patients who were unable to read or understand Dutch | [underlined: BDI, HADS:] Self-report. Completed while receiving treatment. | [underlined: MINI:] Performed by a medical resident who was extensively trained on the MINI by a psychiatrist. For 1:7 patients, MINI interviews were performed by both the medical resident and the psychiatrist (100% Inter-rater reliability). Timing: NR | BDI, HADS = NR; 33.9%
Neitzer, 2012^46^; N = 134; US CA, TX; 2009 | Multisite: outpatient HD units; 48% Female; Age: 59.1(14.7); AA/Black: 22%; Asian: 13%; White: 60%; Other: 4%; Education: NR; HD: 100%; Months on dialysis: Median = 27.5 (2.9-252.2); History of depression: NR | Included: English or Spanish speaking, 18+ years old, due in April to June 2009 for their KDQOL-SF36 assessment.; Excluded: Questionnaires with 50% or more of the questions left blank were considered incomplete and excluded. | [underlined: BDI-FS:] Self-report. Completed during HD treatment. | [underlined: BDI-II:] Completed during HD session. Order of completion was not specified. | BDI-FS≥ 4 = 30.1%; BDI II ≥ 16: 28.7%
^1^Preljevic, 2012^36^; N = 109; Norway | Multisite: hospital-based HD and PD centers; 30.3% Female; Age 57.8(15.7); Race: NR; 69.4% HS or less; HD: 76.6%; PD: 23.3%; Months on dialysis: M=8.5 (3.75-22); History of depression: NR | Included: 18+ years receiving either HD or PD for more than 2 months, were in a stable clinical condition and had adequate Norwegian language skills.; Excluded: Cognitive dysfunction, psychosis or drug/alcohol abuse; hospitalization during the investigation period; however, they could be enrolled 4 weeks or more after discharge from hospital if they were in a stable clinical condition. | [underlined: BDI, CDI, HADS-D:] Self-report. Completed in a standardized sequence during the dialysis treatment for HD patients and during the routine outpatient control for PD patients. | [underlined: SCID-I:] Administered by an experienced psychiatrist who was blinded to each participant’s medical history and scores on all self-report questionnaires. Assessments were conducted during dialysis sessions to standardize the assessment procedure and the time point relative to dialysis treatment. Interviews were audiotaped and 25 randomly selected tapes were scored independently by another psychiatrist to establish inter-rater reliability. The interrater reliability for depressive disorder was excellent (κ=1). Timing: NR | BDI≥16 = 20.8%, CDI≥11 = NR, HADS-D≥8 = 20.1%; 22%; 14.7% MDD
^1^Troidle, 2003^47^; N = 97; US; June 2000-January 2002 | Multisite: CPD and HD units; CP: 46% Female; HD: 40% Female; Age: CPD 55.4(11.3); HD 56(8.6); White: CPD 75%; HD 87%; CPD: 83%; HD 17%; Education: NR; Dialysis duration: NR; History of depression: NR | NR | [underlined: 2 items from the KDQOL SF-36:] Self-report. Likert 1-6. Scored by a social worker. Timing: consecutive | [underlined: BDI:] Self-report. Recorded by a social worker. Timing: consecutive | KDQOL SF-36 = NR; BDI-II ≥11 NR
^1^Van den Beukel,^51^ 2012; N = 133; Netherlands | Multisite: outpatient hospital-based dialysis units; 39% Female; Age: 62(16); Native Dutch: 66%; Education: NR; HD: 72%; Dialysis duration: NR; Previous Depression: 9%; Antidepressant: 6%; Months on dialysis: M=54(65); History of depression: NR | Inclusion: 18+ years of age, ESRD for at least 30 days, able to read the Dutch language and had no significant visual, physical, or cognitive impairment that would prevent completion of the questionnaires; Exclusion: NR | [underlined: MHI5 of the SF-36:] Self-report. Completed during dialysis. Timing: NR | [underlined: BDI/CDI (Dutch Translation)]: Self-report. Completed during dialysis. Timing: NR | MHI5≤70 = 39%; BDI-II ≥16 = 23%, CDI≥10 = 23%
Watnick, 2005^44^; N = 62; US; Portland, OR; July 2003-May 2004 | Multisite: public and private outpatient HD and PD units (including VA); Female: 32%; Age: 63(15); AA/Black: 15%; Hispanic: 5%; Asian: 5%; White: 76%; Education: NR; HD: 95%, PD: 5%; Dialysis duration: NR; History of depression: NR | Inclusion: 18+ years old and had started dialysis therapy more than 90 days before enrollment.; Exclusion: Did not speak English, MMSE ≤17, medical record documentation of a psychiatric diagnosis other than depression, were deemed unable to participate by the dialysis staff, or were scheduled for kidney transplant within the next month. | [underlined: BDI, PHQ-9:] Self-report. | [underlined: SCID-I:] Interviewed by a mental health professional (completed psychology internship), blinded to BDI/PHQ-9 results. Timing: within 2 weeks of index tests. | BDI, PHQ-9 = NR; 19.4%
^1^Wang, 2019^45^; N = 319; China | Multisite: hospital-based HD units; 31.4% Female depressed; 43.78% Female non-depressed; Age: 49.4 (6.04) depressed; 50.92(6.46) non-depressed; Race: NR; HS or less: 51.44% depressed; 57.78% non-depressed; HD:100%; Dialysis duration: NR; History of depression: NR | Inclusion: 18+ years of age; history of maintenance HD >3 months; ability to understand written Chinese, complete the interview and the questionnaire, and provide informed consent; Excluded: documented cognitive impairment, had another primary diagnosis (eg chronic heart failure, cancer, hyperthyroidism), or had been previously diagnosed with depression and other psychiatric disorders | [underlined: BDI, DI-MHD:] Self-report. Timing: 2 weeks after clinical interview | [underlined: SCID-I (ref for BDI):] Administered by a psychologist and a nephrologist. Timing: 2 weeks before index tests.; [underlined: BDI-II (ref for DI-MHD):] Same time as index test. | BDI≥19 = 20.7%, DI-MHD≥25 = 20%; 21.9%

1 Screened for depressive symptoms or milder forms of depression in addition to Major Depressive Disorder.

2 Included cutoff values for both Major Depressive Disorder as well as for milder forms of depression and subclinical symptoms.

Abbreviations: BDI-II = Beck Depression Inventory – II; BDI-FS = Beck Depression Inventory - Fast Screen; CA = California; CDI = Cognitive Depression Index; CES-D = Center for Epidemiologic Studies – Depression Scale; CVD = cardiovascular disease; DI-MHD = Depression Inventory – Maintenance Hemodialysis; ESAS = Edmonton Symptom Assessment System; ESRD = end-stage renal disease; GDS-15= Geriatric Depression Scale-15; HADS-D = Hospital Anxiety and Depression Scale - Depressive Subscale; Ham-D= Hamilton Depression Rating Scale; HD = hemodialysis; HS = high school; ICD-10 = 10th revision of the International Statistical Classification of Diseases and Related Health Problems; KDQOL SF-36 = Kidney Disease Quality of Life Short Form - 36; MDD = major depressive disorder; MHI5 = Mental Health Inventory 5; NR = not reported; MINI = Mini International Neuropsychiatric Interview; MMSE = Mini-Mental Status Examination; NR = Not reported; NC = North Carolina; OR = Oregon; PD = peritoneal dialysis; PHQ-9= Patient Health Questionnaire 9; SCID-I= Structured Clinical Interview for DSM-IV; SF-36 = Kidney Disease Quality of Life Short Form - 36; SRQ = Self-Reporting Questionnaire; TX = Texas; UK = United Kingdom; US = United States; VA = Veterans Affairs

Table 3 Findings of studies examining the diagnostic accuracy of depression screening tools in patients with ESRD

Author, Year N enrolled | Cutoff | Sens (%) | Spec (%) | PPV (%) | NPV (%) | AUC | Summary of Findings
Beck Depression Inventory-II (BDI-II)
Balogun, 2011^39^; N = 96 | ≥10 | 68 | 77 | 57 | 85 | 0.73 | Compared to diagnostic interview, the BDI-II cutoff with the best diagnostic accuracy was ≥10.
Bautovich, 2018^48^; N = 45 | ≥18 | 100 | 90 | 60 | 100 | 0.99 | Compared to diagnostic interview, the BDI-II is an acceptable screening tool, with a cutoff of ≥18.
Chilcot, 2008^53^; N = 40 | ≥16 | 88.9 | 87.1 | 88.8 | 87 | 0.961 | Consistent with previous research, (off dialysis) BDI-II with a cutoff of ≥16 has good diagnostic accuracy.
^2^Grant, 2008^50^; N = 57 | ≥10 | 100 | 50 | 21.9 | 100 | 0.93 | Using the general population cut-off score (≥10), the BDI-II significantly over-diagnosed depression in this HD population. A cutoff of ≥15 is more reliable.
^2^Grant, 2008^50^; N = 57 | ≥15 | 100 | 78 | NR | NR | 0.93 | Using the general population cut-off score (≥10), the BDI-II significantly over-diagnosed depression in this HD population. A cutoff of ≥15 is more reliable.
^2^Grant, 2008^50^; N = 57 | ≥20 | 71.4 | 92 | NR | NR | 0.93 | Using the general population cut-off score (≥10), the BDI-II significantly over-diagnosed depression in this HD population. A cutoff of ≥15 is more reliable.
^1^Hedayati, 2006^33^; N = 98 | ≥14 | 62 | 81 | 53 | 85 | 0.77 | When used for screening, the threshold for depression should be higher for ESRD compared with non-ESRD patients (ie, ≥14).
^1^Loosman, 2010^35^; N = 62 | ≥13 | 75 | 90.2 | 75 | 90.2 | 0.90 | At a cutoff of ≥13, the BDI-II is an effective screening tool for depression in depression in ESRD patients.
^1^Preljevic, 2012^36^; N = 109 | ≥12 | 91 | 63 | 39 | 96 | 0.92 | The BDI-II demonstrated acceptable performance as a screening tool for depression. At a threshold of ≥16 (general population) the BDI-II performed better than the HADS and the CDI; however, a cutoff of ≥17 is more reliable for this population.
^1^Preljevic, 2012^36^; N = 109 | ≥13 | 91 | 68 | 43 | 97 | 0.92
^1^Preljevic, 2012^36^; N = 109 | ≥14 | 86 | 71 | 44 | 95 | 0.92
^1^Preljevic, 2012^36^; N = 109 | ≥15 | 82 | 75 | 46 | 94 | 0.92
^1^Preljevic, 2012^36^; N = 109 | ≥16 | 82 | 87 | 62 | 95 | 0.92
^1^Preljevic, 2012^36^; N = 109 | ≥17 | 82 | 89 | 67 | 95 | 0.92
^1^Preljevic, 2012^36^; N = 109 | ≥18 | 77 | 92 | 71 | 94 | 0.92
^1^Wang, 2019^45^; N = 319 | ≥15 | 87 | 49 | 34 | 93 | 0.84 | A cutoff of ≥19 indicated depression in this population.
^1^Wang, 2019^45^; N = 319 | ≥16 | 87 | 58 | 39 | 94 | 0.84 | A cutoff of ≥19 indicated depression in this population.
^1^Wang, 2019^45^; N = 319 | ≥17 | 87 | 65 | 43 | 94 | 0.84 | A cutoff of ≥19 indicated depression in this population.
^1^Wang, 2019^45^; N = 319 | ≥18 | 87 | 71 | 47 | 95 | 0.84 | A cutoff of ≥19 indicated depression in this population.
^1^Wang, 2019^45^; N = 319 | ≥19 | 83 | 86 | 63 | 94 | 0.84 | A cutoff of ≥19 indicated depression in this population.
^1^Wang, 2019^45^; N = 319 | ≥20 | 74 | 94 | 77 | 92 | 0.84 | A cutoff of ≥19 indicated depression in this population.
Watnick, 2005^44^; N = 62 | ≥16 | 91 | 86 | 59 | 98 | 0.937 | The BDI-II ≥16 is a valid measure for depressive disorders in the dialysis population.
Cognitive Depression Index (CDI)
Bautovich, 2018^48^; N = 45 | ≥11 | 100 | 92 | 67 | 10 | 0.98 | Compared to diagnostic interview, the CDI ≥11 is an acceptable screening tool.
^1^Hedayati, 2006^33^; N = 98 | ≥8 | 50 | 83 | 52 | 82 | 0.76 | When used for screening, the threshold for depression should be higher for ESRD compared with non-ESRD patients. The BDI-II or the CESD have better sensitivity and better agreement (kappa) than the CDI (cutoff ≥8).
^1^Preljevic, 2012^36^; N = 109 | ≥9 | 82 | 79 | 50 | 94 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
^1^Preljevic, 2012^36^; N = 109 | ≥10 | 82 | 86 | 60 | 95 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
^1^Preljevic, 2012^36^; N = 109 | ≥11 | 82 | 93 | 75 | 95 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
^1^Preljevic, 2012^36^; N = 109 | ≥12 | 77 | 95 | 81 | 94 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
^1^Preljevic, 2012^36^; N = 109 | ≥13 | 50 | 98 | 85 | 88 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
^1^Preljevic, 2012^36^; N = 109 | ≥14 | 41 | 98 | 82 | 86 | 0.89 | The CDI (cutoff ≥11) demonstrated acceptable performance as a screening tool for depression. The BDI-II performed better than the CDI.
Center for Epidemiologic Studies – Depression Scale (CES-D)
^1^Hedayati, 2006^33^; N = 98 | ≥18 | 69 | 83 | 60 | 88 | 0.86 | When used for screening, the CESD threshold for depression should be higher (≥18) for ESRD compared with non-ESRD patients.
Geriatric Depression Scale-15 (GDS-15)
Balogun, 2011^39^; N = 96 | ≥5 | 63 | 82 | 60 | 83 | 0.81 | The GDS-15 ≥5 is a valid tool compared to the gold standard.
Hamilton Depression Rating Scale (Ham-D)
^1^Gencoz, 2007^42^; N = 45 | ≥10 | 100 | 80 | 59 | 100 | 85 | The HDRS ≥10 is a reliable and valid instrument that can be used among ESRD patients undergoing HD
Hospital Anxiety and Depression Scale - Depressive Subscale (HADS-D)
^1^Loosman, 2010^35^; N = 62 | ≥6 | 90.5 | 75.6 | 85.7 | 75.6 | 0.89 | The HADS-D ≥6 is an effective screening tool for depression in depression in ESRD patients.
^1^Preljevic, 2012^36^; N = 109 | ≥4 | 100 | 48 | 33 | 100 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥5 | 95 | 60 | 38 | 98 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥6 | 95 | 73 | 48 | 98 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥7 | 86 | 84 | 58 | 96 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥8 | 73 | 87 | 59 | 93 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥9 | 59 | 92 | 65 | 90 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥10 | 59 | 94 | 72 | 90 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
^1^Preljevic, 2012^36^; N = 109 | ≥11 | 50 | 96 | 79 | 88 | 0.91 | At a HADS-D threshold of ≥8 the BDI-II performed better.
Patient Health Questionnaire 9 (PHQ-9)
Watnick, 2005^44^; N = 62 | ≥10 | 92 | 92 | 71 | 98 | 0.94 | The PHQ-9 ≥10 is a valid measure for depressive disorders in the dialysis population.
Self-Reporting Questionnaire (SRQ)
Alsuwaida, 2006^52^; N = 26 | ≥8 | 100 | 50 | 26 | NR | 0.96 | The SRQ has high sensitivity the PPV is poor due to the somatic symptoms in non-depressed patients with ESRD. A cutoff of ≥13 results in an acceptable specificity level without compromising sensitivity.
Alsuwaida, 2006^52^; N = 26 | ≥9/10 | 100 | 68 | 36 | NR | 0.96
Alsuwaida, 2006^52^; N = 26 | ≥11/12 | 100 | 72 | 40 | NR | 0.96
Alsuwaida, 2006^52^; N = 26 | ≥13 | 100 | 82 | 50 | NR | 0.96
Alsuwaida, 2006^52^; N = 26 | ≥14/15 | 75 | 91 | 60 | NR | 0.96
Alsuwaida, 2006^52^; N = 26 | ≥16/17 | 75 | 95.5 | 75 | NR | 0.96
Alsuwaida, 2006^52^; N = 26 | ≥18 | 75 | 100 | 100 | NR | 0.96

1 Screened for depressive symptoms or milder forms of depression in addition to Major Depressive Disorder.

2 Included cutoff values for both Major Depressive Disorder as well as for milder forms of depression and subclinical symptoms.

Abbreviations: AUC = Area under (receiver operating characteristic [ROC]) curve; BDI-II = Beck Depression Inventory – II; CDI = Cognitive Depression Index; CES-D = Center for Epidemiologic Studies – Depression Scale; GDS-15 = Geriatric Depression Scale-15; HADS-D = Hospital Anxiety and Depression Scale - Depressive Subscale; Ham-D = Hamilton Depression Rating Scale; NPV = Negative predictive value; NR = Not reported; PHQ-9 = Patient Health Questionnaire 9; PPV = Positive predictive value; Sens = sensitivity; Spec = specificity; SRQ = Self-Reporting Questionnaire

Diagnostic Accuracy Studies: A Primer

The performance of a diagnostic test is described by its sensitivity and specificity, along with the positive and negative predictive values. Depression assessment tools generate outcomes along a continuous scale, much like a lab test such as the thyroid stimulating hormone. Usually, there is a trade-off between sensitivity and specificity: at lower diagnostic thresholds (ie, lower scores on a depression instrument in which higher scores indicate more symptoms) one is more likely to capture all patients that have depression (ie, higher sensitivity) but there are also likely to be more false positive tests (ie, lower specificity). The area under the receiver operating curve (AUC) describes a test’s overall performance and its ability to correctly distinguish patients with and without disease across a range of diagnostic thresholds. Generally, tests with higher AUC are better able to discriminate patients with and without disease, though tests with similar AUC can still perform differently at different diagnostic thresholds. The choice of diagnostic instrument and diagnostic threshold depends in part on how important it is to detect all patients with disease (which might be very important for treatable and potentially fatal conditions), how important it is to minimize the risk of false positives (ie, because treatment of the condition is potentially harmful, burdensome, or costly), and to what extent the diagnostic test has been evaluated in the population of interest (Veterans in the United States with ESRD, in this case).

### Summary of Findings

#### Diagnostic Accuracy by Screening Tool

##### Beck Depression Inventory-II (BDI-II)

The BDI-II is a widely used, validated 21-item self-report tool designed to assess depression severity in adolescents and adults, and was by far the most widely studied instrument in the ESRD population. It closely mirrors DSM-IV criteria for major depressive disorder, and includes questions related to cognitive, affective, and somatic symptoms.^27^

Table 4 lists the performance characteristics of 5 studies examining the accuracy of the BDI-II in diagnosing Major Depressive Disorder compared to a gold standard clinical interview (eg, SCID-I).^39,44,48,50,53^ Sample sizes ranged from N = 40^53^ to N = 96.^39^ Two of the 5 studies were conducted in the United States.^39,44^ One was a small, multicenter study that included 1 VHA site (N = 62), and reported an optimal BDI-II cutoff of ≥16. Sensitivity was 0.91 and specificity was 0.86, with an AUC of 0.94.^44^ The second was a multicenter study of adults 65 and older (N = 96). At a cutoff of ≥10, sensitivity was 0.68, specificity was 0.77, and reported AUC was 0.73 (see Table 2 for study details).^39^

One study in Table 4 reported BDI-II performance across a range of thresholds.^50^ The threshold that optimized the sensitivity and specificity of the BDI-II for MDD was ≥15, with a reported area under the receiver operating curve (AUC) of 0.93. One study reported an AUC that was much lower than the others.^39^ This study’s population was limited to older adults, and it is possible that age differences may have contributed to the difference in performance characteristics (see Table 2 for study details).^39^

Table 4 Beck Depression Inventory-II (BDI-II) characteristics by threshold among studies screening for Major Depressive Disorder (MDD)

Threshold | Sensitivity (%) | Specificity (%) | PPV (%) | NPV (%) | AUC
≥10^39,50^ | 68 | 77 | 57 | 85 | 0.73
≥10^39,50^ | 100 | 50 | 21.9 | 100 | 0.93
≥15^50^ | 100 | 78 | NR | NR | 0.93
≥16^44,53^ | 88.9 | 87.1 | 88.8 | 87 | 0.961
≥16^44,53^ | 91 | 86 | 59 | 98 | 0.937
≥18^48^ | 100 | 90 | 60 | 100 | 0.99
≥20^50^ | 71.4 | 92 | NR | NR | 0.93

Abbreviations: AUC = Area under (receiver operating characteristic [ROC]) curve; BDI-II = Beck Depression Inventory-II; NPV = Negative predictive value; NR = Not reported; PPV = Positive predictive value

Table 5 also lists performance characteristics for the BDI-II, but unlike the studies in Table 4, these 4 studies screened for depressive symptoms and disorders ranging from subclinical to MDD.^35,36,45,56^ Sample sizes ranged from N = 43^53^ to N = 319.^45^ Only 1 study (N = 98) was conducted in the United States, with 1 of the 3 sites at a VHA.^56^ At a threshold of ≥14, sensitivity was 0.62, specificity was 0.81, and reported AUC was 0.77. The largest study (N = 319), conducted in China, compared the BDI-II (≥19) to the SCID-I as part of a development and validation study for a depression tool designed specifically for patients undergoing maintenance hemodialysis.^45^ Sensitivity, specificity, PPV, NPV, and AUC were 0.83, 0.86, 63%, 94%, and 0.84 respectively (see Table 2 for study details).

Table 5 Beck Depression Inventory-II (BDI-II) characteristics by threshold among studies screening for Major Depressive Disorder (MDD) and less severe depression

Threshold | Sensitivity (%) | Specificity (%) | PPV (%) | NPV (%) | AUC
≥12^36^ | 91 | 63 | 39 | 96 | 0.92
≥13^35,36^ | 75 | 90.2 | 75 | 90.2 | 0.90
≥13^35,36^ | 91 | 68 | 43 | 97 | 0.92
≥14^56,36^ | 62 | 81 | 53 | 85 | 0.77
≥14^56,36^ | 86 | 71 | 44 | 95 | 0.92
≥15^36,45^ | 82 | 75 | 46 | 94 | 0.92
≥15^36,45^ | 87 | 49 | 34 | 93 | 0.84
≥16^36,45^ | 82 | 87 | 62 | 95 | 0.92
≥16^36,45^ | 87 | 58 | 39 | 94 | 0.84
≥17^36,45^ | 82 | 89 | 67 | 95 | 0.92
≥17^36,45^ | 87 | 65 | 43 | 94 | 0.84
≥18^36,45^ | 77 | 92 | 71 | 94 | 0.92
≥18^36,45^ | 87 | 71 | 47 | 95 | 0.84
≥19^45^ | 83 | 86 | 63 | 94 | 0.84
≥20^45^ | 74 | 94 | 77 | 92 | 0.84

Abbreviations: AUC = Area under (receiver operating characteristic [ROC]) curve; BDI-II = Beck Depression Inventory-II; NPV = Negative predictive value; NR = Not reported; PPV = Positive predictive value

##### Cognitive Depression Index (CDI)

The CGI is a subset of the BDI and includes the first 15 of the 21-items included in the BDI, eliminating items related to somatic symptoms. It was developed for use in patients with Chronic Kidney Disease, with the goal of reducing the likelihood of the overdiagnosis of depression.^57^

Three studies compared the performance characteristics of the CGI to a gold standard clinical interview,^36,48,56^ of which only 1 screened for major depressive disorder (N = 45; cutoff ≥10).^48^ Sensitivity and specificity values, and AUC were 0.79, 0.81, and 0.94 respectively (see Tables 2 and 3).^48^

The 2 studies screening for the range of depressive symptoms and diagnoses examined cutoff values of ≥8 (N = 98)^56^ and ≥11 (N = 109).^36^ Sensitivity values were 0.50^56^ and 0.82,^36^ specificity was 0.83^56^ and 0.93,^36^ and AUC was 0.76^56^ and 0.89 (see Tables 2 and 3).^36^ Of note, 1 study^36^ examined both the BDI at a threshold of ≥16 and CDI (≥11) and found that the BDI performed better.

##### Hospital Anxiety and Depression Scale – Depression Subscale (HADS-D)

The Hospital Anxiety and Depression Scale – Depression Subscale (HADS-D) is a widely-used 21-item scale that includes ratings of physical, cognitive, and affective symptoms of depression.^34^

Two studies examined the performance characteristics of the HADS-D in patients with ESRD.^35,36^ Both studies also screened for less severe depression diagnoses and/or subclinical symptoms. One study (N = 62) examined a cutoff value of ≥6 and found sensitivity, specificity, and AUC values of 0.91, 0.76, and 0.89 respectively. ^35^ The other (N = 109), examined a cutoff value of ≥8 and reported sensitivity, specificity, and AUC values of 0.73, 0.87, and 0.91 respectively. Of note, this study also examined the BDI and found that it performed better (≥16; see Tables 2 and 3).^36^

##### Center for Epidemiologic Studies – Depression Scale (CES-D)

The CES-D is a widely used 20-item tool that was revised in 2004 and evaluates depressive symptoms across 4 factors: depressive affect, well-being, somatic symptoms, and interpersonal relations.^32^

A 3-center multisite study (1 VHA; N = 98)^56^ compared the CES-D (≥18) to the SCID-I for MDD and other less severe forms of depression and subclinical symptoms. Sensitivity, specificity, and AUC were 0.69, 0.83, and 0.89 respectively (see Tables 2 and 3).

##### Hamilton Depression Rating Scale (Ham-D)

The Ham-D is a 17-item rating scale that assesses the frequency and intensity of depressive symptoms. It was developed in 1960, and last revised in 1967.^41^

A single small study (N = 45) conducted in Turkey compared the HAM-D (≥10) to the SCID-I in patients with ESRD undergoing hemodialysis and screened for the range of depressive symptoms and disorders. Reported sensitivity was 1.00, specificity, 0.80, and AUC was 0.85 (see Tables 2 and 3).^42^

##### Geriatric Depression Scale-15 (GDS-15)

The GDS-15 is a shortened version of the original 30-item GDS, which assesses depressive symptoms in older adults and was developed in 1982.^37,38^

One study (N = 96) compared the GDS-15 (≥5) in older adults with ESRD to a gold standard clinical interview for MDD. Sensitivity was 0.62, specificity was 0.82, and AUC was 0.81 (see Tables 2 and 3).^39^

##### Patient Health Questionnaire-9 (PHQ-9)

The PHQ-9 was developed in 2001 to be a short form assessment of depression and severity. It is widely used in the US and internationally.^43^

One small multisite study (N = 62) that included a VHA center examined the PHQ-9 (≥10) compared to the gold standard SCID for MDD. Sensitivity and specificity were both 0.92, and AUC was 0.94 (see Tables 2 and 3).^44^

##### Self-Reporting Questionnaire (SRQ)

The SRQ was developed by the World Health Organization (WHO) to screen for a range of mental health disorders.^58^

A single very small study (N = 26) conducted in Saudi Arabia compared the SRQ (≥13) to the gold standard SCID-I in patients with ESRD for MDD. Sensitivity, specificity, and AUC were 1.00, 0.82, and 0.96 respectively (see Tables 2 and 3).^52^

#### Screening Tools Compared to Other Tools

Seven studies used other established tools (ie, BDI-II, HADS) as reference standards.^40,45–47,49,51,53^ Table 6 lists their performance characteristics. Only 2 studies screened for MDD specifically, both evaluating shortened versions of the BDI-II (BDI-II Fast Screen [BDI-FS], CDI).^46,53^ Of the 2, the BDI-FS,^59^ a 7-item version of the BDI-II that excludes somatic symptoms and was designed to screen for MDD in medical patients, had high sensitivity and specificity as compared to the BDI-II ≥16.^46^ Among those screening for the range of depressive symptoms and disorders, the GDS-15 (≥6)^46^ and the Depression Inventory – Maintenance Hemodialysis (DI-MHD; ≥25), a scale developed specifically for patients with ESRD,^45^ appear to perform well in this population (see Table 2 for study details).

Table 6 Studies comparing a depression tool to another validated depression tool

Author, Year N enrolled | Cutoff | Sens (%) | Spec (%) | PPV (%) | NPV (%) | AUC | Summary of Findings
Beck Depression Inventory – Fast Screen (BDI-FS)
Neitzer, 2012^46^; N = 134 | ≥4 | 97.2 | 91.8 | 81.4 | 98.9 | 0.98 | Reference standard: BDI-II ≥16
Cognitive Depression Index (CDI)
Chilcot, 2008^53^; N = 40 | ≥10 | 77.8 | 80.6 | 77.7 | 80.6 | 0.94 | Reference standard: BDI-II ≥16
Depression Inventory – Maintenance Hemodialysis (DI-MHD)
^1^Wang, 2019^45^; N = 319 | ≥23 | 97 | 55 | 84 | 89 | 0.94 | Reference standard: BDI-II ≥19
^1^Wang, 2019^45^; N = 319 | ≥24 | 97 | 72 | 90 | 91 | 0.94 | Reference standard: BDI-II ≥19
^1^Wang, 2019^45^; N = 319 | ≥25 | 97 | 86 | 95 | 93 | 0.94 | Reference standard: BDI-II ≥19
^1^Wang, 2019^45^; N = 319 | ≥26 | 93 | 90 | 96 | 84 | 0.94 | Reference standard: BDI-II ≥19
^1^Wang, 2019^45^; N = 319 | ≥27 | 85 | 90 | 95 | 70 | 0.94 | Reference standard: BDI-II ≥19
Edmonton Symptom Assessment System (ESAS) – single question
^1^Collister, 2019^49^; N = 50 | ≥2 | 81 | 74 | NR | NR | 0.81 | Reference standard: HADS ≥6.
Geriatric Depression Scale-15 (GDS-15)
^1^Giordano, 2007^40^; N = 31 | ≥6 | 94 | 85 | 89 | 92 | 0.95 | Reference standard: BDI-II ≥14.
Kidney Disease Quality of Life Short Form - 36 (KDQOL SF-36) “Have you felt downhearted and blue?”
^1^Troidle, 2003^47^; N = 97 | ≤3 | 82 | 69 | NR | NR | NR | Reference standard: BDI-II ≥11.
Kidney Disease Quality of Life Short Form - 36 (KDQOL SF-36) “Have you felt so down in the dumps so that nothing could cheer you?”
^1^Troidle, 2003^47^; N = 97 | ≤3 | 65 | 67 | NR | NR | NR | Reference standard: BDI-II ≥11.
Mental Health Inventory 5 (MHI5)
^1^Van den Beukel, 2012^51^; N = 133 | ≥66 | 67 | 78 | NR | NR | 0.82 | Reference standard: BDI-II ≥16 (≥66+) and CDI≥10 (≥74+)
^1^Van den Beukel, 2012^51^; N = 133 | ≥70 | 77 | 72 | 44 | 91 | 0.82 | Reference standard: BDI-II ≥16 (≥66+) and CDI≥10 (≥74+)
^1^Van den Beukel, 2012^51^; N = 133 | ≥74 | 83; 81 CDI | 65; 65 CDI | NR | NR | 0.82; 0.81 CDI | Reference standard: BDI-II ≥16 (≥66+) and CDI≥10 (≥74+)
^1^Van den Beukel, 2012^51^; N = 133 | ≥78 | 90 | 54 | NR | NR | 0.82 | Reference standard: BDI-II ≥16 (≥66+) and CDI≥10 (≥74+)
^1^Van den Beukel, 2012^51^; N = 133 | ≥82 | 93 | 45 | NR | NR | 0.82 | Reference standard: BDI-II ≥16 (≥66+) and CDI≥10 (≥74+)

1 Screened for depressive symptoms or milder forms of depression in addition to Major Depressive Disorder.

Abbreviations: AUC = Area under (receiver operating characteristic[ROC]) curve; BDI-II = Beck Depression Inventory – II; BDI-FS = Beck Depression Inventory - Fast Screen; CDI = Cognitive Depression Index; DI-MHD = Depression Inventory – Maintenance Hemodialysis; ESAS = Edmonton Symptom Assessment System; GDS-15 = Geriatric Depression Scale-15; HADS-D = Hospital Anxiety and Depression Scale - Depressive Subscale; KDQOL-36 = Kidney Disease Quality of Life Short Form - 36; MHI5 = Mental Health Inventory 5; NPV = Negative predictive value; NR = Not reported; PHQ-9 = Patient Health Questionnaire 9; PPV = Positive predictive value; Sens = sensitivity; Spec = specificity; SRQ = Self-Reporting Questionnaire

### Ongoing studies

No ongoing studies were identified.

## KEY QUESTION 2 What is the impact of screening for depression in patients with ESRD on intermediate and/or patient outcomes?

No studies were identified to provide evidence for Key Question 2.

## KEY QUESTION 3 What is the effectiveness of depression treatment in patients with ESRD and depression?

We identified 20 RCTs examining pharmacological or nonpharmacologic interventions for the treatment of depression in patients with ESRD. Five trials examined selective serotonin reuptake inhibitors (SSRIs), including 3 of sertraline and 1 each of fluoxetine and citalopram; 2 trials examined nutritional supplements including omega-3 fatty acids and high-dose, oral vitamin D3. Thirteen trials examined nonpharmacologic interventions including 5 trials of CBT, 2 acupressure trials, and 1 each of Benson Relaxation Technique, exercise training, guided imagery, hope therapy, Latihan Pasrah Diri, Mindfulness-based Stress Reduction (MBSR), and Quran readings. All studies were of participants receiving HD. A single study included both patients receiving HD and PD (see Table 7).

### Summary of findings

#### A Pharmacological treatment

We identified 7 RCTs examining pharmacological interventions for depression in participants with ESRD. There was low SOE that there is no difference in depression severity reduction between sertraline and CBT, though both are beneficial. Regarding dietary supplements, there was moderate SOE that long-term, high-dose Vitamin D3 is not effective for reducing depression severity in ESRD patients. Findings for all other pharmacotherapies were insufficient to draw conclusions.

##### SSRIs

The data to guide the treatment of depression in patients with ESRD with SSRIs is limited. We identified 5 RCTs investigating the effects of SSRIs on depression – 3 comparing SSRIs to placebo and 2 comparing SSRIs to an active comparator.

###### SSRIs versus placebo

Studies comparing SSRIs to placebo report conflicting findings and provide insufficient evidence for the use of SSRIs to treat depression in patients with ESRD. A small (N = 14), poor-quality RCT^60^ conducted in 1997 compared fluoxetine to placebo. At 4 weeks, participants receiving fluoxetine reported a significantly larger reduction in depressive symptoms from baseline, compared to placebo. However, by 8 weeks the differences were no longer significant. A more recent, fair-quality RCT (N = 30)^61^ in England compared sertraline to placebo and found that although both groups reported a reduction in depressive symptoms, there was no difference between groups at the end of treatment (6 months) or 6-month follow up. A second, larger fair-quality RCT (N = 50)^62^ conducted in Iran also compared sertraline to placebo. Participants who received sertraline reported a significant reduction in depressive symptoms at 12 weeks (see Tables 7 and 8). Overall, these fair- to poor-quality studies provide insufficient evidence for the use of SSRIs to treat depression in patients with ESRD (see Table 10). Studies were hampered by small sample sizes, and differences in depression assessment tools and statistical analyses (see Table 9).

###### SSRIs versus active comparators

A recent fair-quality multi-site US study by Mehrotra et al (N = 120)^63^ compared sertraline to CBT. The primary outcome was clinician-rated depression measured with the QIDS-C, and both groups improved over 12 weeks. However, the sertraline group experienced significantly greater improvement (effect estimate: −1.85; 95% CI: −3.55 to −0.16]). For the secondary endpoint of self-rated depression (BDI-II) the difference between the groups was not significant (effect estimate: −2.9 [95% CI: −6.7 to 0.8]). The strength of evidence for this comparison was low (see Tables 7, 8, and 9).

A poor-quality RCT (N = 44)^64^ conducted in Iran provides insufficient evidence for the comparison of citalopram to “psychological training” in depressed patients with ESRD. Although both arms experienced a reduction in depressive symptoms, there was no difference between citalopram and the comparator (see Tables 7, 8, and 9).

##### Supplements

Two RCTs compared supplements to placebo for the treatment of depression in ESRD patients. A large (N = 746), fair-quality, 52-week RCT^65^ conducted in Southeast China compared ESRD patients (treated with either HD or PD) receiving either high-dose vitamin D3 or placebo. Both arms reported a reduction in depression symptoms at 52 weeks with no significant difference between groups (see Tables 7 and 8). Given the size and quality of the study, the strength of evidence is moderate that long-term, high-dose vitamin D3 is an ineffective treatment for depression in patients with ESRD (see Table 9).

A single, poor-quality RCT (N = 54),^66^ conducted in Iran, examined the effect of omega-3 fatty acids versus placebo. Findings indicate a significant reduction in depression symptoms in the treatment arm at 4 months, and no change was associated with placebo. The evidence is insufficient to form conclusions (see Tables 7, 8, and 9).

#### B Non-pharmacological treatment

We identified 13 RCTs examining non-pharmacological interventions for depression in participants with ESRD. There was low SOE that CBT is more effective than other psychotherapy for depression severity and QOL, but not for suicide risk. CBT was also more effective than placebo for depression severity and QOL (low SOE). There was also low SOE for acupressure reducing depression severity when compared with usual treatment or sham acupressure. Findings for all other non-pharmacological interventions were insufficient to draw conclusions.

##### Cognitive Behavioral Therapy

Five RCTs investigated CBT for the treatment of depression in patients with ESRD.

###### CBT versus active comparator

We identified 3 RCTs that compared CBT to an active comparator for the treatment of depression in patients with ESRD. A fair-quality RCT (N = 90)^67^ conducted in Brazil compared group CBT to individualized psychotherapy for participants with MDD, and found a greater reduction in depression symptoms (both clinician and self-reported) associated with CBT (BDI-II: P = 0.001 after 3 months of treatment, P = 0.002 at 9 months follow-up; MINI: P < 0.001 after 3 months of treatment. P = 0.031 at 9 months follow-up; low SOE). In addition, participants receiving CBT also experienced a significant within group decrease in suicide risk and improved on several quality-of-life domains over the study period, while the those assigned to psychotherapy did not. However, the between-group difference in suicide risk reduction was nonsignificant (low SOE). At the end of the study period, there was a significant difference favoring CBT in several quality of life domains (ie, burden of kidney disease, quality of social interaction, sleep, overall health, and the mental health; low SOE; see Tables 7, 8, and 9).

Two other trials compared CBT to an active comparator. A poor-quality Jordanian RCT (N = 130)^68^ compared CBT to psychoeducation, and while both groups reported a reduction in depression symptoms, the psychoeducation group experienced greater improvement. The strength of evidence for this comparison is insufficient. The third study by Mehrotra and colleagues^63^ was also included in the pharmacotherapy section because it examined CBT versus sertraline for treatment-seeking participants with ESRD and depression. For the primary outcome of clinician-rated depression severity, both groups experienced improvement, but sertraline was more effective than CBT. However, there was no difference between the CBT and sertraline groups in self-reported depression severity, and the strength of evidence was low (see Tables 7, 8, and 9).

###### CBT versus control

Two fair-quality RCTs^69,70^ provide low-strength evidence of CBT’s benefit when compared with waitlist control. A fair-quality, New York-based RCT (N = 65) examined individual CBT during dialysis and found a greater magnitude of reduction in depression symptoms (P = 0.03) and a significant improvement in quality of life (P = 0.04) among those receiving CBT compared with those on the waitlist.^69^ The study also found that fluid adherence was improved for the CBT group at all timepoints, but the strength of evidence for that comparison is insufficient. The second study was a fair-quality RCT (N = 60) examining once-weekly group CBT sessions following dialysis in those with mild-moderate depression in a Mexican ESRD population. Findings also indicate a significant reduction in depression and increased quality of life (low SOE; see Tables 7, 8, and 9).^70^

##### Acupressure

Two RCTs contribute to low-strength evidence that acupressure is more effective than control for reducing depression severity in ESRD patients. Both studies used similar acupressure procedures. A fair-quality, 3-arm, Iranian RCT (N = 96)^71^ compared acupressure to sham acupressure (ie, pressure applied 1 cm from the acupressure point), and usual care. Participants receiving acupressure reported a significantly greater reduction in depression symptoms compared to both sham and usual care (no difference between sham and usual care). A second 3-arm poor quality RCT (N = 108)^72^ compared acupressure to transcutaneous Electrical Acupoints Stimulation (TEAS) and usual care in participants in Northern Taiwan. TEAS was applied to the same acupressure points and is theorized to have a similar effect to acupressure and acupuncture.^72^ Findings indicate a greater reduction in depressive symptoms and fatigue, and an improvement in sleep quality associated with both acupressure and TEAS than usual care (no significant difference between acupressure and TEAS). The evidence examining acupressure for fatigue and sleep quality is insufficient to draw conclusions (see Tables 7, 8, and 9).

##### Other treatments

We included RCTs of 7 other therapies: Benson Relaxation Technique,^73^ exercise training,^74^ guided imagery,^75^ hope therapy,^76^ Latihan Pasrah Diri (LPD),^77^ MBSR,^78^ and Quran readings for Muslim patients (see Tables 7, 8, and 9).^79^ All were small, single trials with methodological issues, and the evidence was insufficient for all of these treatments.

#### C Pharmacological and non-pharmacological treatments combined

No trials addressing the combination of pharmacological and non-pharmacological treatments were identified.

### Ongoing studies

We identified 3 relevant trials of depression treatments for patients with ESRD, all of which have not yet reported results or been published (see Table 10 for details).

Table 7 Characteristics of randomized controlled trials of interventions for depression in ESRD outpatients

Author, Year Intervention, N enrolled Country/US region, years of enrollment | Study setting, clinical characteristics, demographics | Inclusion Criteria/Depression Diagnosis | Depression Screening Tool(s) and their application | Baseline Depression Score; Mean ± SD, T vs C
Pharmacological
Blumenfield, 1997^60^; Fluoxetine; N = 14; New York, NY; Years: NR | 2 sites: Hospital dialysis centers; Demographics: NR | [underlined: Included]: 18-70 yrs old, normal liver function, score of at least 16 for MDD by Hamilton scale.; [underlined: Excluded]: chronic illness other than ESRD and DM, suicidal risk, Axis 1 dx except MDD, psychotropic meds other than Lorazepam, pregnant or not on contraception if child bearing age, MAOI in the past 2 weeks or participation in any drug trial within 4 weeks; [underlined: Depression diagnosis:] MDD | Psychiatrist administered HAM-D for dx; BDI; MADRS; Depression Scale of Brief Symptom Inventory; self-report VAS for severity of depression | NR
Friedli, 2017^61^; Sertraline; N = 30; England; April 2013 - May 2015 | Multisite (5): Renal units; 12% Female; Age: 61.7 (13.2); Race: 67% white, 13% AA, 13% Asian, 7% mixed | [underlined: Included]: BDI-II score ≥16, diagnosed with mild to moderate MDD with MINI, and MADRS score ≥18; [underlined: Excluded]: current or past 3 months tx for depression (antidepressants or psychologic therapies), planned living donor kidney transplant within trial period, prognosis of <1 year, several associated medical conditions (Hepatic impairment, Hepatitis B and C, HIV/AIDS, Creutzfeldt–Jakob disease, pregnancy or childbearing potential and not using adequate birth control, substance dependency, psychosis, personality disorder, dementia, or panic disorder with the exception of other anxiety disorders), and contraindicated medications (Monoamine oxidase inhibitors, Pimozide, Triptans, Antipsychotics, Dopamine antagonists, Tramadol, Linezolid, Warfarin), those with severe depression or suicidal ideation, and cognitive impairment on the Folstein MMSE (cut point of 23).; [underlined: Depression diagnosis:] MDD | BDI-II; MINI; MADRS patient completed BDI-II, then interviewed by psychiatrist for MINI | [underlined: MADRS]: 24.5 (4.5) vs 25.3 (4.2)
Gharekhani, 2014^66^; Omega-3 fatty acid; N = 54; Tehran, Iran; Year: NR | 2 sites: HD Centers; Duration: 70.7 +/− 45.1 mos; 4 hrs, 2-3x/wk; 48% Female; Age: 56.8 ± 13.09 yrs | [underlined: Included]: Adults, TIW HD for at least 3 months and all had same HD rx; [underlined: Excluded]: BDI-II<16; pregnancy; current inflammatory or infectious diseases; malignancy; prognosis of <4 months; asthma or COPD; other known psychiatric disorders; hypothyroidism; hemoglobinopathies; concurrent involvement in other research studies; history of medical or surgical illness in past 3 months; previous medication or HD noncompliance; malabsorption syndrome; coagulopathies or increased risk of bleeding; need to take anticoagulant medications including warfarin; intake of omega-3 fatty acids supplement in recent 3 months; hypersensitivity to fish or fish-derived products; concurrent use of corticosteroid, immunosuppressive, immunomodulator, anti-depressant, antiepileptic (except gabapentin), anti-psychotic, or nonsteroidal anti-inflammatory medications; [underlined: Depression diagnosis:] Any | BDI-II; application details NR | [underlined: BDI-II]: 23.52 ± 7.49 (Median/IQR: 22 (17, 28)) vs 21±4.72 (Median/IQR: 21 (16.50, 22.75)).
Hosseini, 2012^64^; Citalopram; N = 44; Iran; Years NR | Single-site: hospital HD center; 55% female; Age: 52.3 ± 15.6 | [underlined: Included]: HADS≥8; [underlined: Excluded]: history of psychiatric disorders, stressors other than ESRD in past 6 months, new anxiety episode during study, based on the stress events table by Holmz-Rahe, any change occurred in the hemodialysis schedule, starting other psychiatric therapies during the study, those not completing all training sessions.; [underlined: Depression diagnosis:] Any | HADS: completed twice by the patients under the supervision of a psychiatrist, once before the random allocation of the patients and once months after the start of interventions | [underlined: HADS:] 9.42 ± 3.11 vs 9.58 ± 3.47
Mehrotra, 2019^63^; Sertraline vs CBT; N = 120; US: NM, TX, WA; 2017 | Multisite (3 states): 41 dialysis facilities Median time since starting dialysis (IQR), mo: 31 (44) Mean hemodialysis treatment time per session (±SD), h: 3.9 ± 0.4; 43% Female; Age: 51 ± 13; Race: 43% white; 28%; Black; 28% Hispanic; 8% Native Amer; 12% other; Education: 40% ≤ high school; History of major depression: 42% | [underlined: Included]: 21 ≥ y/o, ESRD, On HD ≥3 months, MDD or dysthymia (BDI-II ≥15, then confirmed by MINI); [underlined: Excluded]: suicidal, receiving intensive psychotherapy for depression, or using medications with potential antidepressant effects at effective therapeutic doses, and those with cognitive impairment, present or past psychosis, or alcohol or substance use disorder; [underlined: Depression diagnosis]: MDD or dysthymia | BDI-II and MINI for screening. QIDS-SR during trial, and QIDS-C and BDI-II at 12 weeks. Final QIDS-C and BDI-II by computer-assisted telephone interviewing | [underlined: QIDS-C] mean (range): SERT 10.9 (9.6 to 12.1) vs CBT 12.2 (11.0 to 13.5); [underlined: BDI-II] mean (range): SERT 25.8 (23.3 to 28.4) vs CBT 26.2 (23.6 to 28.8)
Taraz, 2013^62^; Sertraline; N = 50; Tehran, Iran; Years NR | Single site: outpatient HD clinic; HD for 4 hrs 3x/wk 43%; Time on HD (months): 42 (59) Female; Age: 60 (22); all others NR | [underlined: Included:] 18 - 80 y/o, HD ≥3 months using arteriovenous fistula, depression diagnosis: BDI-II ≥16; [underlined: Excluded:] inflammatory cause of ESRD, autoimmune diseases, active infections, malignancy, severe mental illness, cognitive dysfunction, hemorrhage/clotting disorders, hypersensitivity to sertraline, treatment with antibiotics, non-steroidal anti-inflammatory drugs, steroids, immunosuppressives, or antidepressant medications within 1 month before the study.; [underlined: Depression diagnosis:] Any | [underlined: BDI-II]; application details NR | [underlined: BDI-II:] 29 (13) vs 23 (11); P = 0.243
Wang, 2016^65^; Vitamin D3; N = 746; Southeast China; Years NR | 3 sites: Dialysis centers HD and PD Outpatient; 39% Female; Age: 54% 18-64; 46% 65+; Other demographics: NR | [underlined: Included]: ESRD, current conventional maintenance PD (3 exchanges a day) or HD (3x/wk, 4–4.5 hrs/session) ≥3 months, age ≥18 years, 15 to 30 ng/mL plasma 25(OH)D BDI-II cutoff: 16; [underlined: Excluded]: cognitive deficits such as considerable memory loss, confusion/dementia, and intellectual disability; illiteracy or inability to answer the questionnaire; antidepressants in 2 years before study; presence of severe depressive symptoms before dialysis; [underlined: Depression diagnosis:] MDD, vascular depression | [underlined: BDI-II-II]: Structured interviews were conducted by 2 experienced psychiatrists independently to determine diagnoses and severity of depression for each patient. | [underlined: BDI-II]: 22.7 ± 4.3 vs 21.9 ± 5.4 (P = 0.31)
Non-pharmacological
Al Saraireh, 2018^68^; CBT vs PSE; N = 130; Jordan, 2017 | Multisite: 5 hospital dialysis units; Dialysis duration: NR; ~50% Female; Age: 52 ± 10.7; Education: 71% ≤ high school Employment: 82% unemployed; Race/Insurance NR | [underlined: Included:] diagnosis of chronic kidney failure; chronic dialysis ≥1 year; verbal comprehension/communication; [underlined: Excluded:] on antidepressants; [underlined: Depression diagnosis:] NR | [underlined: HAM-D:] Data collectors with previous experience on psychiatric research read the items of the instrument for the participants and documented their response. | [underlined: HAM-D:] PSE 19.6 ± 5.4 vs CBT 19.5 ± 5.4 No difference: t(103) = −0.13; P = 0.89
Babamohamadi, 2017^79^; Quran; N = 60; Iran, year NR | Single site: hospital dialysis ward; 42.6% Female; Age: 53.3 (11.4); Race: NR; Education: 75% less than diploma; Employment: NR (55.6% “poor”); Insurance: NR | [underlined: Included]: 18-65 y/o; BDI-II score ≥20; command of Arabic; HD for ≥6 months; hemodynamic stable; [underlined: Excluded]: using antidepressants, acute mental problems, history of mental illness, impaired consciousness, hearing impairment Depression diagnosis: moderate | [underlined: BDI-II-II:] self-completed before start of dialysis/first session, and again after the last one | [underlined: BDI-II-II:] 33.6 (6.7) vs 29.3 (9.0); mean difference: −4.3 (95% CI: −8.7 to 0.0) P = 0.05
Beizaee, 2018^75^; Guided Imagery; N = 80; Iran, 2015-2016 | Single-site: HD center; Sex: 41.25% Female; Age: 47.21(8.34); Education: 46.25%; Secondary Employment: 25% unemployed | [underlined: Included]: HD 3x/wk for ≥6 months; 35-65 y/o; read/write in Farsi, intact cognitive functions based on Abbreviated Mental Test (AMT); [underlined: Excluded]: hearing impairment, history of psychiatric disorders, taking tranquillizer or sedative drugs 4h before the intervention, and hemodialysis instability.; [underlined: Depression diagnosis]: Any | [underlined: HADS:] completed before and after intervention | [underlined: HADS:] 10.82 ± 2.70 vs 11.55 ± 2.29
Cukor, 2014^69^; N = 65; CBT; Brooklyn, NY, year NR | 2 sites: dialysis units; 72.7% Female; Age: NR; Race: 93.9% Black; Education: 11.2 (3.4) yrs; Employment: 83.4% Unemployed; Insurance: NR | [underlined: Included:] ESRD with HD for ≥6 months; BDI-II score ≥10; [underlined: Excluded:] current hospitalization, altered mental status (MMSE <23), psychosis, current substance abuse, current ongoing psychotherapy, change in psychotropic medication in last 6 months, lack of English proficiency to participate in talk therapy; [underlined: Depression diagnosis:] Moderate | [underlined: BDI-II-II] (self-reported), HAMD (clinician assessed), and; [underlined: SCID-I] (major depression): Applied before randomization and after 3 and 6 months | [underlined: SCID-I] % w/major depression: 54.5 vs 42.2; [underlined: BDI-II:] 25.3 (9.3) vs 21.4 (8.9); [underlined: HAM-D:] 15.0 (6.2) vs 13.5 (5.0)
Duarte, 2009^67^; CBT; N = 90; Brazil, year NR | 2 sites: dialysis units; HD: 3x/wk for 4 hrs avg.; 63.4% Female; Age: 52.4±15.9; Race: 78.1% white; Education: 83% ≤ primary school; Employment/Insurance: NR | [underlined: Included:] ESRD with HD for ≥3 months; MINI MDD diagnosis; [underlined: Excluded:] transplant scheduled, current hospitalization, psychiatric comorbidity (Axis I DSM-IV), cognitive or mental retardation, current substance abuse, or unstable clinical condition; [underlined: Depression diagnosis:] MDD | [underlined: BDI-II] and [underlined: MINI]: questionnaires administered and rated by trained psychologist immediately before the start of the intervention, after 3 months, and at the end of 9 months | [underlined: BDI-II]: 24.2±9.7 vs 27.3±10.7 (P = 0.149); [underlined: MINI]: 6.4±1.3 vs 6.4±1.2 (P = 0.955)
Heshmatifar, 2015^73^; Benson Relaxation Technique; N = 70; Iran, 2013 | Single site: hospital HD unit; HD: 3x/wk; 18% Female; Age: 9% 18-35; 33% 35-45; 45% 45-55; 15% 55-65; Race: NR; Education: 94% ≤ high school; Employment: 42%; Unemployed; Insurance: NR | [underlined: Included]: 18-65 y/o; HD 3x/wk for ≥6 months; regular patient of the center; [underlined: Excluded]: mental/muscular disorders or severe physical disabilities; mental health medication use; history of depression or hospitalization due to mental disorders before CHD and hemodialysis; history of accidents or unpleasant events over the past 6 months; kidney transplant or PD; death; [underlined: Depression diagnosis]: Any | [underlined: BDI-II-II]: no description of application, but did say that patients’ depression had to be confirmed by a neurologist | [underlined: BDI-II]: 32.46±9.86 vs 30.58±9.24
Kalani, 2019^71^; Acupressure; N = 96; Iran, 2011 | 3 sites: HD centers; 44% Female; Age: 53.4±13.9; Race: NR; Education: 31% non-literate; Employment: 50%; Unemployed; 41% retired; Insurance: NR | [underlined: Included]: ESRD diagnosis; Age 18+; HD for ≥3 months; BDI-II score ≥10; mental and psychological ability to participate; [underlined: Excluded]: wounds or fractures at acupressure points; used complementary medicine in last 3 months; lower extremity amputation; unstable physiological symptoms; high creatinine and high urea; acute mental and psychological problems for the past 6 months; [underlined: Depression diagnosis]: Any | [underlined: BDI-II]: pts fill before and after intervention | [underlined: BDI-II]: Tx 27.5 ± 9.1 vs PBO 25.7 ± 7.7 vs C 24.6 ± 8.6 (not sig diff)
Kouidi, 2010^74^; Exercise training; N = 50; Greece, year NR | Single site: hospital renal unit; HD: 3x/wk for 4 hrs; 41.6% Female; Age: 46.3 ± 11.2; Education: 10.2 ± 3.4 yrs; Employment: 16.6%; Unemployed; Race/Insurance: NR | [underlined: Included]: ESRD; 4 hrs HD 3x/wk for ≥6 months; [underlined: Excluded]: history, clinical signs, or symptoms of psychiatric, neurological, cardiologic, or pulmonary disorders; diabetes mellitus; significant electrolytic instability or undisciplined patients; musculoskeletal limitation or other medical problems contraindicating participation in an ET program; [underlined: Depression diagnosis]: NR (mild-severe) | [underlined: BDI-II and HADS]: administered to all patients at the beginning and at the end of the study by the same physician, who was not familiar with the patients | [underlined: BDI-II]: 22.29 ± 6.71 vs 22.30 ± 6.81; [underlined: HADS]: 10.63 ± 2.60 vs 10.40 ± 2.50
Lerma, 2017^70^; CBT; N = 60; Mexico City, MX Year NR | 2 sites: HD units; HD: 3x/wk for 3-4hrs; 51.6% Female; Age: 41.8 ± 14.7; Education: 35.5% elementary; Employment: 25.8%; Unemployed; Race/Insurance: NR | [underlined: Included]: ESRD; mild-moderate depression; literate; no psychiatric illness; regular attendance of HD sessions 3-4 hrs HD 3x/wk for ≥6 months; [underlined: Excluded]: BDI-II > 29 points were referred for appropriate psychiatric evaluation and care.; [underlined: Depression diagnosis]: mild-moderate (BDI-II score of 10–29 points) | [underlined: BDI-II:] questionnaires completed in privacy with supervision of a trained technician | [underlined: BDI-II:] 13.6 ± 7.6 vs 15.8 ± 10.0
Rahimipour, 2015^76^; Hope therapy; N = 50; Iran, year NR | Multi-site: hospitals; HD: 2-3x/wk for 4 hrs; 48% Female; Age: 47.82 (15.12); Race/Education/Employment/Insurance: NR | [underlined: Included]: 18–65 y/o; HD 2-3x/wk for ≥3 months; not taken medication for depression, anxiety, or stress; [underlined: Excluded]: NR; [underlined: Depression diagnosis]: NR | [underlined: DASS-21] questionnaire; application details NR | [underlined: DASS-21]:13.36 ± 3 vs 13.64 ± 3.5; No difference (t = 0.3; P = 0.76)
Thomas, 2017^78^; MBSR; N = 41; Montreal, Canada, 2016 | Single site: hospital HD unit; 33% Female; Age: 65 ± 13; Race: 49% white, 51% nonwhite; Education: 63% ≤ high school; Employment/Insurance: NR | Included: On maintenance HD; spoke English or French; had depression (PHQ-9 score ≥6) and/or anxiety symptoms (GAD-7 score ≥6); Excluded: sig cog impairment; psychosis; suicidal ideation/intent; [underlined: Depression diagnosis]: Any | [underlined: PHQ-9:] Participants completed questionnaires with an independent assessor | [underlined: PHQ-9:] 12.7 ± 4.2 vs 11.9 ± 5.8
Tsay, 2004^72^; Acupressure; N = 108; Northern Taiwan, Year NR | 4 sites: hospital dialysis centers; Duration HD: 50.06 (44.15) months; 66% Female; Age: 58.16 (12.19); Employment: 76.1%; Retired or Unemployed; Race/Education: NR | [underlined: Included:] ESRD diagnosis; Age 18+; HD for ≥3 months; fatigue; PSQI score ≥5; BDI-II score ≥10; [underlined: Excluded:] lower-extremity amputations, comorbid psychiatric disorders, congestive heart failure, COPD, insulin-dependent diabetes, neuromuscular disease, systemic lupus erythematosus, rheumatoid arthritis, cancer, regular steroid therapy, or use of anti-hypertension medications.; [underlined: Depression diagnosis:] Any | [underlined: BDI-II]; application details NR | [underlined: BDI-II:] Acupressure 20.37±10.65 vs TEAS 18.20 ± 11.11 vs C 21.61 ± 11.69
Widyaningrum, 2013^77^; Latihan Pasrah Diri; N = 36; Java, Indonesia, 2012 | Single site: hospital HD unit HD: 2x/wk; 61.1 % Female; Age: 50.06 (7.39); Education: 77.8% ≤ high school; Insurance: 5.6% uninsured; Employment/Race: NR | [underlined: Included:] CKD patients on 2x/wk HD for ≥3 months; BDI-II ≥16, 18-60 y/o; [underlined: Excluded:] taking antidepressant or psychotropic meds, undergoing psychotherapy, or unable to do relaxation exercises; [underlined: Depression diagnosis:] Any | [underlined: BDI-II]; application details NR | [underlined: BDI-II]: 23 ± 5.34 vs 23.39 ± 5.02

Abbreviations: BDI-II = Beck Depression Inventory-II; CKD = chronic kidney disease; COPD = Chronic Obstructive Pulmonary Disease; DASS = Depression, Anxiety, and Stress Scale; DM = diabetes mellitus; DSM-IV = Diagnostic and Statistical Manual-IV; ESRD = end-stage renal disease; ET = Exercise training; GAD = Generalized Anxiety Disorder; HADS = Hospital Anxiety and Depression Scale; Ham-D =Hamilton Depression Rating Scale; HD = hemodialysis; MADRS = Montgomery–Åsberg Depression Rating Scale; MAOI = Monoamine oxidase inhibitors; MDD = Major Depressive Disorder; MINI = Mini International Neuropsychiatric Interview; MMSE = Mini-Mental Status Examination; MX = Mexico; NM = New Mexico; NR = not reported; NY = New York; P = p-value; PD = peritoneal dialysis; PHQ-9 = Patient Health Questionnaire-9; PSE = psychoeducation; PSQI = Pittsburgh Sleep Quality Index; QIDS-C = Quick Inventory of Depressive Symptomatology - Clinician; SD = standard deviation; SERT = Sertraline RCT = randomized controlled trial; TEAS = Transcutaneous Electrical Acupoint Stimulation; TX = Texas; US = United States; WA = Washington; wk = week

Table 8 Efficacy of interventions for depression in ESRD patients from randomized controlled trials

Author, Year N randomized (T vs C), Duration of treatment and follow-up | Intervention description | Comparator description | Findings, Treatment vs Comparator
Author, Year N randomized (T vs C), Duration of treatment and follow-up | Intervention description | Comparator description | Depression | Other outcomes | Quality
PHARMACOLOGICAL
SSRIs vs control
Blumenfield, 1997^60^; N = 14; Fluoxetine vs placebo; 7 vs 7; Tx = 8 weeks; F/U = 8 weeks | [underlined: Fluoxetine]: 20mg/day for 8 weeks | Matched placebo | No difference between groups at 8 wks. FLU sig better than PBO at 4 weeks on BDI, BSI, and electronic VAS, but not other scales. HAM-D only reported end of study difference: not significant.; [underlined: Mean change from baseline (at 4 wks; at 8 wks):]; [underlined: BDI:] −12 vs −4.17 (P = 0.05); −9.57 vs −8.8 (P = 0.91).; [underlined: BSI:] −6.29 vs 0.2 (P = 0.04); −4.43 vs −3.2 P = 0.88; [underlined: HAM-D]: no 4 wk assessment; −9.00 vs −7.5 (P = 0.72); [underlined: MADRS]: −7.20 vs −6.75 (P = 0.93); −11.14 vs −6.67 (P = 0.45); [underlined: VAS]: −210.0 vs −58.3 (P = 0.37); −303.0 vs −140 (P = 0.45); [underlined: Electronic VAS]: −262.4 vs 5.6 (P = .05); −389.0 vs −87.8 (P = 0.13) | NA | Poor
Friedli, 2017^61^; Sertraline vs placebo; 15 vs 15; Tx = 6months; F/U = 6months | [underlined: Sertraline:] 100mg/day (50mg/day to start. Dose could be increased to max at 2 and 4 months) | Matched placebo | No treatment effect; [underlined: MADRS between group difference at 6 months:] −0.67 (−5.7 to 4.4); NS; Within groups decrease significant for both groups; [underlined: Mean change at study end]; [underlined: MADRS:] −14.5 (95% CI: 20.2 to −8.8) vs −14.9 (95% CI: −18.4 to −11.5); [underlined: BDI-II:] −15.7 (95% CI: −24.3 to −7.1) vs −13.0 (95% CI: 19.6 to −6.4); between groups diff NS | NA | Fair
Taraz, 2013^62^; Sertraline vs placebo; 25 vs 25; Tx = 12 weeks; F/U = 12 weeks | [underlined: Sertraline]: 100mg/day (50mg/day for 1^st^ 2 weeks) | Matched placebo | Favors SERT; [underlined: BDI-II scores] (Baseline, 6 weeks, 12 weeks, Baseline to 12 weeks): Sertraline: 29 (13); 21 (11.5); 15 (5.5); −11.3±5.8 vs Placebo: 23 (11); 22.5 (8.5); 22.5 (9); −0.5±5, Comparison baseline to 12 weeks between groups (P = 0.001). | NA | Fair
SSRIs vs active comparator
Hosseini, 2012^64^; Head-to-head Citalopram vs psychological training; 22 vs 22; Tx = 3 months; F/U = 3 months | [underlined: Citalopram:] 20mg/day | [underlined: Psychological training:] 6 1-hr sessions explaining kidney anatomy; physiopathology and causes of kidney failure; treatment modalities with their dis/advantages; HD mechanisms; required care for HD patients; stages of adaptive reaction; problem solving, stress management, and muscle relaxation techniques. | [underlined: Post-intervention HADS]: 6.26 ± 4.18 (P = 0.001) vs 7.33 ± 4.80 after training (P = 0.04).; No difference between groups (P = 0.16).; Between groups mean differences also NS (P = 0.65) | NA | Poor
Mehrotra, 2019^63^; Head-to-head Sertraline vs CBT; 60 vs 60; Tx = 12 weeks; F/U = 12 weeks | [underlined: Sertraline]: 200mg/day unless limited by AEs (titration began at 25 mg/d and adjusted each visit) | [underlined: CBT]: 10 60-minute sessions during HD for 12 weeks.; Therapy included standard components of the intervention (psychoeducation, behavioral intervention, cognitive intervention, and health behavior modification) adapted for maintenance hemodialysis (adherence to dialysis and challenging disease-specific cognitive distortions and maladaptive thought patterns) | Sertraline more effective than CBT for physician reported, but not self-reported, depression after sensitivity analyses with multiple imputation.; [underlined: QIDS-C scores:] 5.9 ± 4.5 vs 8.1 ±5.1; Effect estimate: −1.85 (95% CI: −3.55 to −0.16); [underlined: BDI-II scores]: 14.1 (95% CI: 11.2 to 17.0) vs 18.7 (95% CI: 15.2 to 22.2.; Effect estimate: −2.9 (95% CI: −6.7 to 0.8) | NA | Fair
Supplements
Gharekhani, 2014^66^; Omega-3 fatty acid vs placebo; 27 vs 27; Tx = 4 months; F/U = 4 months | [underlined: Omega-3 fatty acids]: 1,800 mg/day (as 6 soft-gel capsules, each containing 180 mg EPA and 120 mg DHA, 2 capsules taken 3x/day) for 4 months | Matched placebo: Paraffin oil capsules | Favors Omega-3; [underlined: Mean end of study BDI-II:] 13.44 ± 5.66 vs 20.33 ± 7.56.; [underlined: Diff:] −10.08 ± 8.07 vs −0.88 ± 8.41; P = 0.001; [underlined: Within groups:] Sig decrease (P < 0.001) vs ND | NA | Poor
Wang, 2016^65^; Vitamin D3 vs placebo; 373 vs 373; Tx = 52 weeks; F/U = 52 weeks | [underlined: High-dose Oral Vitamin D3]: 52-week treatment of 50,000 IU/wk.; Treatment time 7-9:00 PM. | Matched placebo | No between groups difference in delta values.; [underlined: Within group BDI-II scores baseline to end of study]: 22.7 ± 4.3 to 19.6 ± 3.7; P = 0.021 vs 21.9 ± 5.4 to 20.8 ± 5.1; P = 0.033 | NR | Fair
NON-PHARMACOLOGICAL
Al Saraireh, 2018^68^; CBT vs PSE (head-to-head); 65 vs 65; Tx = 12 weeks; F/U = 12 weeks | [underlined: CBT]: 7 individual 1-hr sessions following the traditional CBT sessions protocol | [underlined: Psychoeducation] (PSE): 7 individual 1-hr sessions. The intention of psychoeducation is to educate people about their disease, its treatment, and rehabilitation. Moreover, this technique should promote acceptance of the disease, active participation of the patient in the treatment process, and learning different strategies to deal with the problems caused by the disease. | Both groups experienced significant decrease in depression scores.; [underlined: Post-test HAM-D scores]: 15.0 (5.5) vs 11.1 (2.3).; Between groups depression scores favored PSE (t = 4.68; P < 0.01) over CBT. | NR | Poor
Babamohamadi, 2017^79^; Quran vs TAU; 30 vs 30; Tx = 1 mo; F/U = 1 mo | [underlined: Quran]: Listen to audio of Quran recitation on headphones for 20 minutes, beginning 5 minutes before dialysis | TAU | Favors Quran.; [underlined: Post-test BDI-II scores]: 14.5 ± 4.8 vs 31.6 ± 9.2; P < 0.0001.; Significant between-subjects treatment effect, independent of age (F = 9.3, P = 0.004, Cohen’s d = 0.85). | NA | Poor
Beizaee, 2018^75^; GI vs TAU; 40 vs 40; Tx = 4 weeks; F/U = 4 weeks | [underlined: Guided Imagery:] 3x/wk for 4 weeks administered by certified psychologist 30 mins prior to HD session; Audio recording of nature sounds. Told to breathe, relax, and imagine they are in the place with the sounds (ie, waterfall, sea waves, jungle, etc) | TAU, nearly silent environment | [underlined: Post-test HADS scores]: 10.02 ± 2.58 vs 11.65 ± 2.33 | [underlined: SBP]: Mean Before 129.22 ± 12.70 vs 132.85 ± 13.22; After 121.75 ± 12.73 vs 134.87 ± 12.68; [underlined: DBP]: Before 82.50 ± 11.32 vs 81.75 ± 8.51; After 81.00 ± 10.32 vs 81.87 ± 8. 14; [underlined: HR]: Before 77. 95 ± 6. 97 vs 75. 42 ± 8.56; After 73.75 ± 6.25 vs 77.22 ± 7.92 | Fair
Cukor, 2014^69^; CBT vs waitlist (crossover); 38 vs 27; Tx = 3 months; F/U = 6 months | [underlined: CBT:] Individual 60min; CBT chairside during dialysis; CBT modified for pop. 10 sessions over 3 months | Wait-list control | Favors tx first compared to wait list. Mean change score during treatment was −11.7 points (SD 1.5; P, 0.001) (raw mean change from 24.7 [SD 9.8] to 11.7 [SD 9.8]) among those receiving treatment first, and −4.8 points (SD 1.4; P < 0.001) for those receiving treatment after completing the waitlist (raw mean change from 14.5 [SD 8.5] to 9.1 [SD 6.5]) There was also significant mean change in BDI-II score in the untreated group during the waitlist period (−6.7 points [SD 1.7]; P < 0.001) (raw mean change from 21.9 [SD 8.9] to 14.5 [SD 8.5]).; [underlined: BDI-II]: The magnitude of BDI-II improvement was significantly greater in the intervention group than it was in patients in the intervention waitlist condition (P = 0.03); [underlined: HAM-D]: The difference in mean change score between treated and untreated groups was highly significant (P < 0.001).; [underlined: SCID-I]: Between groups not reported | [underlined: QOL]: favors tx, irrespective of when it occurs. Treatment effect = +12.0 points (SD 3.4; P = 0.003) (raw mean score change from 99.5 [SD 27.9] to 115.3 [SD 25.5]) for tx first vs +11.3 points (SD 3.7; P = 0.01) (raw mean change from 110.6 [SD 25.1] to 119.7 [SD 24.7]) for those treated after waitlist.; Between group difference in mean change score sig P = 0.04; Significant increase in QOL associated with treatment, but not waitlist. P = 0.04.; [underlined: Fluid Adherence]: favors tx irrespective of when it occurs: model-estimated mean change score during treatment −1.3%Δkg/d (SD 0.3; P = 0.001) (raw mean change from 4.0 [SD 2.0] to 2.8 [SD 1.6]) for tx first and −1.1%Δkg/d (SD 0.3; P = 0.001) (raw mean change from 3.6 [SD 2.0] to 2.5 [SD 2.0]) among waitlist first. difference between tx groups and control sig P = 0.002 | Fair
Duarte, 2009^67^; CBT vs psychotherapy; 46 vs 44; Tx= 12 weeks; F/U = 9 months | [underlined: CBT]: Group CBT sessions (with psychologist specialized in CBT) 90 minutes 1x/wk for 12 weeks; Pts not on HD during sessions; Structured, manualized methodology; Followed by 6 months maintenance w/monthly mtgs | [underlined: Individualized psychotherapy] with psychologist (routinely available in dialysis unit) 30-50 min 1x/wk for 12 weeks;; Followed by as-needed psychological care for 6 months | Both groups experienced improvement on BDI-II and MINI (P < 0.001), but T’s improvement was greater.; [underlined: BDI-II]: After 3 months 14.1 ± 8.7 vs 21.2 ± 9.1 (P = 0.001); After 9 months 10.8 ± 8.8 vs 17.6 ± 11.2 (P = 0.002); [underlined: MINI]: the mean change from baseline ± SE favored intervention.; After 3 months: 4.5 ± 0.4 vs 2.1 ± 0.6; P < 0.001; After 9 months: 4.4 ± 0.4 vs 2.9 ± 0.5; P = 0.031 | [underlined: Suicide Risk] Module (MINI): No between groups difference.; Baseline 2.2 ± 5.1 vs 1.4 ± 3.5, P = 0.287; After 3 months 1.2 ± 4.2 vs 0.7 ± 1.9, P = 0.433; After 9 months 0.6 ± 1.2 vs 0.6 ± 2.0, P = 0.947; Overall reduction, within group comparison: Significant reduction within T group (P = 0.007) vs C (P = 0.130); [underlined: QOL]: CBT group significantly improved several dimensions of KDQOL. Between groups sig improvement in burden of kidney disease, quality of social interaction, sleep, overall health, and mental component summary dimensions. | Fair
Heshmatifar, 2015^73^; BRT vs TAU; 35 vs 34; Tx = 1 month; F/U = 1 month | [underlined: Benson relaxation technique (BRT)]: Pts attend training sessions, then demonstrate technique to researcher during each of their HD sessions. The rest of the practices were done without supervision using a pamphlet and CD. Performed 20 minutes 2x/day for 1 month. | TAU | Only T group’s scores decreased. The difference between groups was significant (P = 0.01). | NA | Poor
Kalani, 2019^71^; Acupressure vs Sham vs TAU; 32 vs 32 vs 32; Tx = 4 weeks; F/U = 4 weeks | [underlined: Acupressure]: Applied during 1st 2hrs of HD. 3x/wk for 4 weeks. to both the legs, both the arms, and the back. the main acupressure points included SP6, ST36 GB34, K1, BL23 and HT7. Each session lasted 20 minutes; 2 minutes for the primary surface stroke to relax the solidity and the remaining 18 minutes for pressing the 6 points (3 minutes for each point). average of 3–4 kg pressure | [underlined: Sham]: Same as acupressure group except pressure applied 1cm from actual acupressure points.; [underlined: Control]: TAU | Post-test: Tx 20.6 vs PBO 25.5 vs C 24.9 significant difference between T and other groups (P = 0.001 for both); No difference between PBO and C (P = 0.220). | NA | Fair
Kouidi, 2010^74^; ET vs control; 25 vs 25; Tx = 1 year; F/U = 1 year | [underlined: Exercise Training (ET) program]: 3x/wk 60-90 min. during 1st 2 hrs of HD session physician and trainer supervised sessions: warm-up, cycling, strengthening, and cool-down | Sedentary control | Favors ET in both BDI-II and HADS scores (P < 0.001) | [underlined: Heart rate variability] (HRV) Indices: SDNN, MSSD, pNN50, LF, HF, and LF/HF all significantly increased in exercise group, but not controls. After intervention exercise group was significantly better in all variables P < 0.001 | Poor
Lerma, 2017^70^; CBT vs waitlist; 38 vs 22; Tx = 5 wks; F/U = 9 wks | [underlined: CBT]: 5, group Cognitive Behavioral Intervention sessions (2hrs) 1x/wk after HD session 3 techniques: 1. Behavioral activation; 2. Deep breathing and muscle relaxation; 3. Cognitive restructuring | Wait list | BDI-II after 5 weeks (end of intervention): 10.2 ± 8.2 vs 15.0 ± 10.9; P = 0.084 BDI-II after 9 weeks (followup): 7.1 ± 7.2 vs 14.7 ± 9.7; P = 0.003.; Significant overall within group reduction in scores for tx (<0.001), but not controls (0.866).; Between groups RR of reducing depressive symptoms = 1.7; Adjusted RR between groups for depression = 0.33 (33% clinical utility, 95% CI: 0.05 to 0.55) | [underlined: Overall QOL] (by PLC) favors treatment: Baseline: 99.4 ± 21.3 vs 91.5 ± 19.5; P = 0.203; After 5 weeks:109.6 ± 21.1† vs 94.0 ± 21.0; P = 0.016; After 9 weeks: 112.5 ± 23.8 vs 91.3 ± 22.5; P = 0.004; Overall within group P = 0.001 vs P = 0.663.; Cohen’s d = 0.93 (large) | Fair
Rahimipour, 2015^76^; Hope therapy vs control; 25 vs 25; Tx = 8 weeks; F/U =12 weeks | [underlined: Hope therapy:] Sessions utilizing Schneider’s hope therapy theory 1x/wk for 8 weeks 1-1.5 hr during 1st 2hrs of dialysis administered by researcher | [underlined: Control:] Listening session with researcher’s coworker in which pts could talk about their disease and problems 1x/wk for 8 weeks | Immediately after 8wk-intervention (t = 12.75; P < 0.001), and at 1-month follow-up (t = 13.83; P < 0.001) | NA | Poor
Thomas, 2017^78^; MBSR + psychoed vs TAU + psychoed; 21 vs 20; Tx = 8 weeks; F/U = 8 weeks | [underlined: MBSR:] guided, chairside meditative practices 10–15 minutes 3x/wk during hemodialysis sessions 4 meditation techniques drawn from mindfulness-based cognitive therapy (body scan, guided meditation, silent meditation, and gentle arm movements); [underlined: Both control and intervention] groups received psychoeducational literature on anxiety and depression. | TAU. [underlined: Both control and intervention] groups received psychoeducational literature on anxiety and depression. | No significant change in PHQ-9: −3.0±3.9 vs 2.0±4.7; P = 0.45 | NA | Fair
Tsay, 2004^72^; Acupressure vs TEAS vs control; 36 vs 36 vs 36; Tx = 4 weeks; F/U = 4 weeks | [underlined: Acupressure:] applied for 15min 3x/wk for 4 weeks 3 min massage, then 4 acupoints (specific points in paper) treated for 3 min each with finger force 3-4kg by investigators and RAs who had received training from Chinese medicine physician vs [underlined: Transcutaneous Electrical Acupoint Stimulation (TEAS)]: applied for 15min 3x/wk for 4 weeks 3 min massage, then 4 acupoints (specific points in paper) treated for 3 min each with 2hz/100hz alternating every 3 seconds applied with paired skin electrodes on acupoints | Control group (not described) | Acupressure and TEAS are similarly effective, and significantly more effective than no intervention (P = 0.009 and P = 0.008 respectively). No difference between acupressure and TEAS (P = 0.95) | [underlined: Fatigue] (by PFS): Baseline Acu 5.92 ± 1.39 vs TEAS 5.60 ± 1.30 vs C 6.01 ± 1.60; Follow-up Acu 4.61 ± 1.72 vs TEAS 4.70 ± 1.50 vs C 5.70 ± 1.80. Post-hoc analysis found significantly lower levels in Acu (P = 0.006) and TEAS (P = 0.02) when compared with controls. No difference between Acu and TEAS; [underlined: Sleep quality] (by PSQI): Baseline Acu 8.85 ± 4.50 vs TEAS 7.12 ± 4.51 vs C 9.35 ± 3.48; Follow-up Acu 7.80 ± 4.00 vs TEAS 6.32 ± 4.55 vs C 9.75 ± 4.65. Compared to controls significantly better with Acu (P = 0.05) and TEAS (P = 0.016). No difference between Acu and TEAS | Poor
Widyaningrum, 2013^77^; LPD vs control; 18 vs 18; Tx= 3 weeks; F/U= 3 weeks | [underlined: Latihan pasrah diri (LPD)]: method combining relaxation and remembrance by focusing practice on breathing and words in the dhikr (relaxation and repetitive prayer) for evoking relaxation response.; 2x/day for 21 days | Control group (not described) | Significantly decreased BDI-II scores within both groups, and greater in LPD, but between group difference not significant (P = 0.201) | [underlined: QOL] (by KDQOL-SF36): significantly greater pre-post change associated with LPD vs control in sleep and overall health. No other differences were significant. | Poor

Note. See Appendix D for details regarding quality assessment.

Abbreviations: AE = adverse event; BDI-II = Beck Depression Inventory; BRT = Benson relaxation technique; BSI = ; CBT = Cognitive Behavioral Therapy; CKD = chronic kidney disease; DASS = Depression, Anxiety, and Stress Scale; DBP = diastolic blood pressure; DSM = Diagnostic and Statistical Manual of Mental Disorders; ESRD = end-stage renal disease; ET = exercise training; FLU = fluoxetine; HADS = Hospital Anxiety and Depression Scale; HAM-D = Hamilton Depression Rating Scale; HD = hemodialysis; HR = heart rate; HRV = heart rate variability; KDQOL-SF = Kidney Disease Quality of Life Short Form; LPD = Latihan Pasrah Diri; MBSR = mindfulness-based stress reduction; MINI = Mini International Neuropsychiatric Interview; NR = not reported; NS = not significant; P = p-value; PBO = placebo; PD = peritoneal dialysis; PFS = Piper Fatigue Scale; PSE = psychoeducation; PHQ = Patient Health Questionnaire; PLC = Profile of Quality of Life in the Chronically Ill; PSQI = Pittsburgh Sleep Quality Index; QIDS-C = Quick Inventory of Depressive Symptomatology - Clinician; QOL = quality of life; RR = relative risk; RCT = randomized controlled trial; SCID-I = The Structured Clinical Interview for DSM-IV Axis I Disorders; SERT = sertraline; SPB = systolic blood pressure; SSRI = Selective serotonin reuptake inhibitor; TAU = treatment as usual; TEAS = Transcutaneous Electrical Acupoint Stimulation

Table 9 Summary of the evidence on interventions for depression in patients with ESRD

Outcome | Conclusion | Strength of Evidence (Justification)^*^
SSRIs vs controls (k = 3, n = 94)
Depression severity | [underlined: Fluoxetine] ^60^; No benefit (k = 1, n = 14); [underlined: Sertraline] ^61^ ^,^ ^62^; Mixed findings (k = 2; n = 80) | Insufficient (NC, SLM)
SSRIs vs active comparator (k = 2; n = 164)
Depression severity | [underlined: Sertraline vs CBT] ^63^; Benefit for both; no difference between groups (k = 1, n = 120) | Low (SLM, UC)
Depression severity | [underlined: Citalopram vs psychological training] ^64^; Benefit for both; no difference between groups (k = 1, n = 44) | Insufficient (SLH, UC)
Supplements vs placebo (k = 2; n = 800)
Depression severity | [underlined: Omega-3 Fatty Acids] ^66^; Increased benefit (k = 1, n = 54) | Insufficient (NP, SLH, UC)
Depression severity | [underlined: High-dose Vitamin D3] ^65^; No benefit (k = 1, n = 746) | Moderate (SLM, UD, UC)
CBT vs active comparator (k = 2; n = 220)
Depression severity | [underlined: CBT vs psychoeducation] ^68^; Benefit for both, but favored psychoeducation (k = 1, n = 130) | Insufficient (SLH, UC)
Depression severity | [underlined: CBT vs psychotherapy] ^67^; Benefit for both, but favored CBT (k = 1, n = 90) | Low (SLM, UC)
Suicide risk | [underlined: CBT vs psychotherapy] ^67^; Benefit in intervention but not control group; no difference between groups (k = 1, n = 90) | Low (SLM, UC)
QOL | [underlined: CBT vs psychotherapy] ^67^; Increased benefit for some domains of KDQOL (k = 1, n = 90) | Low (SLM, UC)
CBT vs control (k = 2; n = 125)^69,70^
Depression severity | Increased benefit (k = 2; n = 125) | Low (SLM)
QOL | Increased benefit (k = 2; n = 125) | Low (SLM)
Fluid Adherence | Increased benefit (k = 1; n = 65)^69^ | Insufficient (SLM, UC)
Acupressure vs control (k = 2; n = 204)
Depression severity^a^ | [underlined: Acupressure vs TAU] ^71^ ^,^ ^72^; Increased benefit (k = 2; n = 204); [underlined: Acupressure vs sham] ^71^; Increased benefit (k = 1; n = 96) | Low (SLM)
Fatigue | [underlined: Acupressure vs TAU] ^72^; Increased benefit (k = 1, n = 108) | Insufficient (SLH, UC)
Sleep quality | [underlined: Acupressure vs TAU] ^72^; Increased benefit (k = 1, n = 108) | Insufficient (SLH, UC)
Acupressure vs active comparator (k = 1, n = 108)
Depression severity | [underlined: Acupressure vs TEAS] ^72^; Benefit for both; no difference between groups | Insufficient (SLH, UC)
Fatigue | [underlined: Acupressure vs TEAS] ^72^; Benefit for both; no difference between groups | Insufficient (SLH, UC)
Sleep quality | [underlined: Acupressure vs TEAS] ^72^; Benefit for both; no difference between groups | Insufficient (SLH, UC)
Benson Relaxation Technique vs control (k = 1; n = 70)^73^
Depression severity | Increased benefit | Insufficient (SLH, UC)
Exercise training vs control (k = 1; n = 50)^74^
Depression severity | Increased benefit | Insufficient (SLH, UC, UP)
HRV | Increased benefit | Insufficient (SLH, UC, UP)
Guided Imagery vs TAU (k = 1; n = 80)^75^
Depression severity | Unclear effect | Insufficient (SLM, UC)
Vital signs | Unclear effect | Insufficient (SLM, UC)
Hope therapy vs active control (k = 1; n = 50)^76^
Depression severity | Increased benefit | Insufficient (SLH, UC, UP)
LPD vs control (k = 1; n = 36)^77^
Depression severity | No benefit | Insufficient (SLH, UP, UC)
QOL | No benefit | Insufficient (SLH, UP, UC)
MBSR vs TAU (k = 1; n = 41)^78^
Depression severity | No benefits | Insufficient (SLM, UP, UC))
Quran vs TAU (k = 1; n = 60)^79^
Depression severity | Increased benefit | Insufficient (SLH, UC, UP)

a Some participants are represented more than once

* The overall quality of evidence for each outcome is based on the consistency, coherence, and applicability of the body of evidence, as well as the internal validity of individual studies. The strength of evidence is classified as follows:^29^

- High = Further research is very unlikely to change our confidence on the estimate of effect.
- Moderate = Further research is likely to have an important impact on our confidence in the estimate of effect and may change the estimate.
- Low = Further research is very likely to have an important impact on our confidence in the estimate of effect and is likely to change the estimate.
- Insufficient = Any estimate of effect is very uncertain.

Abbreviations: CBT = cognitive behavioral therapy; HRV = heartrate variability; k = number of studies; LPD = Latihan Pasrah Diri; MBSR = mindfulness-based stress reduction; n = sample size; NC = not consistent; ND = not direct; NP = not precise; SLH = study limitations high; SLM = study limitations medium; SSRI = Selective Serotonin Reuptake Inhibitor; TAU = treatment as usual; UC = unknown consistency; TEAS = Transcutaneous Electrical Acupoint Stimulation; UD = unclear directness; UP = unclear precision

Table 10 Ongoing randomized controlled trials of depression treatments in patients with ESRD

PI/Study Director (Registration); Study Design; Sponsors; Estimated Study Completion | Study Title | Purpose of Study | Participants; Intervention(s)/Comparator | Outcomes and Timing
Looper, K (NCT02686333 (https://clinicaltrials.gov/ct2/show/NCT02686333)); - RCT; - Sponsored by the Lady Davis Institute, Jewish General Hospital, Montreal, Canada; - June 2019 | Meditation Intervention for the Treatment of Depression and Anxiety Symptoms in Patients Undergoing Dialysis: A Randomized Control Trial | Examine the use of brief meditation interventions for patients with symptoms of anxiety and depression who are undergoing dialysis | 50 Patients on maintenance hemodialysis with anxiety and depression; 10-15 minutes of individually conducted medication practices (silent meditations, guided meditations, body scans, gentle arm movement exercises) vs mental health lit. and TAU | Secondary: Change in PHQ-9 after 8 weeks
Rej, S (NCT03406845 (https://clinicaltrials.gov/ct2/show/NCT03406845)); - Head-to-head RCT; - Sponsored by the Lady Davis Institute, Jewish General Hospital, Montreal, Canada; - June, 2019 | Brief Chair-Side Mindfulness Intervention for Depression and Anxiety Symptoms in Patients Undergoing Dialysis: A Pilot Randomized Control Trial with an Active Control Group | Examine the acceptability of meditation Examine techniques versus health promotion in people receiving dialysis who have anxiety or depression | 60 adult patients on maintenance HD with depression and/or anxiety; Tailored, chair-side mindfulness intervention based on Mindfulness-based Cognitive Therapy (MBCT) vs group health promotion based on the Health Enhancement Program (HEP) as active control for 8 weeks | PHQ-9 depression scores at 8 weeks and 6 months follow-up; Other outcomes: sleep, QOL, perceived stress and improvement, social difficulties, HRV, ESAS
Khatami, SMR (IRCT201201175113N2); - Single-blind RCT; - Nephrology Research Center, Tehran University of Medical Sciences, Iran; - Started 2012, end NR | A Clinical Trial Comparing the Effect of Omega-3 with Sertraline and Placebo on Depression General Health Conditions Among Dialysis Patients | Compare the efficacy of Omega-3 and Sertraline for depression in ESRD patients | 75 adult HD patients with depression; Omega-3 1500mg vs Sertraline 50-150mg vs placebo for 3 months | HADS at 4, 8, and 12 weeks

Abbreviations: ESAS = Edmonton Symptom Assessment Scale; ESRD = end-stage renal disease; HADS = Hospital Anxiety and Depression scale; HD = hemodialysis; HRV = heartrate variability; NR = not reported; PHQ = Patient Health Questionnaire; QOL = quality of life; RCT = randomized controlled trial; TAU = treatment as usual

## KEY QUESTION 4 In patients with ESRD and depression, what are the potential harms of screening and treatment?

Five pharmacological trials reported adverse events. Sertraline trials most commonly reported AEs. Some harm outcomes were more common with Sertraline than placebo including study dropouts due to AEs, nausea, and other nonserious AEs, but none of these were more severe than for the general population. There were also some dropouts due to AEs in the trial of high-dose Vitamin D3. There were no serious AEs in the non-pharmacological trials.

### A Screening

No included studies reported on harms of screening.

### B Treatment

#### Summary of Findings

Five pharmacological trials reported adverse events (AEs). Sertraline trials most commonly reported AEs. Some harm outcomes were more common with Sertraline than placebo including study dropouts due to AEs, nausea, and other nonserious AEs, but none of these were more severe than for the general population. There were also some dropouts due to AEs in the trial of high-dose Vitamin D3. There were no serious AEs in the non-pharmacological trials.

#### Pharmacological

##### SSRIs

A wide range of AEs were reported by participants in both the treatment and control groups in 4 trials examining SSRIs. Across trials, AEs were not consistently reported. The following AEs were reported in 2 or more trials: nausea, infections, headaches, dizziness or hypotension, gastrointestinal issues, sexual dysfunction, and insomnia. Three of 4 trials reported nausea as a common AE.^60–62^ Other reported AEs included major bleeding, cardiac and nervous system conditions.^63^ Three sertraline trials performed analyses of adverse events between groups. One trial reported significantly more study dropouts due to adverse or serious adverse events associated with sertraline (33% vs 0%; P = 0.04).^61^ A second trial reported no difference in the frequency of adverse events, with the exception of more frequent reports of nausea associated with sertraline (P = 0.033).^62^ In the third trial, there were no significant differences between SAEs associated with sertraline and CBT (RD = 0.08; 95% CI: −0.11 to 0.28). However, there were more nonserious AEs associated with sertraline (RD = 0.65: 95% CI: 0.25 to 1.05).^63^ Only the trial of citalopram included no reported SAEs.^64^ Overall, AEs for SSRIs in ESRD patients with depression were no more severe than reported by the general population treated with SSRIs. There is no evidence that SSRIs are more harmful for this population.

##### Supplements

No serious AEs associated with omega-3 fatty acids were reported.^66^ Adverse events associated with high dose vitamin D3, including joint pain, diarrhea, nausea, and vomiting resulted in study withdrawal of 5 participants.^65^ No statistical analyses were performed, and the evidence is insufficient to form conclusions.

#### Non-pharmacological

Four trials of non-pharmacological interventions reported on adverse events. No adverse events were reported in trials of Latihan Pasrah Diri,^77^ MBSR,^78^ and exercise training.^74^ One CBT trial reported no discontinuations due to serious adverse events.^67^ With the exception of exercise training, due to the nature of the interventions the potential for serious adverse events is unlikely; however, the evidence is insufficient to draw any conclusions.

## KEY QUESTION 5 Do the benefits or harms of screening differ by subpopulation?

We identified 1 study that examined differences in the benefits or harms of depression screening in patients with ESRD. A small (N = 43) multisite diagnostic accuracy study conducted in UK outpatient hemodialysis units compared depression screening (BDI, CDI) completed on and off dialysis.^53^ Findings indicated that there was generally a high level of agreement, particularly among depressed patients. However, non-depressed patients had higher mean overall BDI-II (9.6[6.2] versus 7.3[5.7], P = 0.007) and somatic symptom item scores (4.4[2.5] versus 3.3[2.1], P = 0.01) on assessments completed while undergoing dialysis.

## KEY QUESTION 6 Do the benefits or harms of treatment differ by subpopulation?

Three trials examined differences in the benefits or harms of interventions for the treatment depression in patients with ESRD by subpopulation. Interventions examined were omega-3 fatty acids,^66^ high-dose vitamin D3,^65^ and CBT.^69^

### Patient Characteristics

Two trials explored differences in effect by patient clinical and demographic characteristics. A large, multisite fair-quality trial (N = 746) of high-dose vitamin D3 found no differences in effect by age or gender, body mass index (BMI), or plasma albumin level. However, findings did indicate that among participants with vascular depression, and not major depressive disorder, those who received Vitamin K reported a significantly greater reduction in depressive symptoms at one year than those receiving placebo.^65^ The second was a small (N = 54), poor-quality trial examining the use of omega-3 fatty acids. It found no significant difference in benefits or harms by age, gender, baseline depression severity, nor length of time on hemodialysis (see Table 8 and 9, and Appendix E for more detail).^66^

### Timing and Type of Follow-up

A small, fair-quality trial (N = 65)^69^ comparing CBT to waitlist control examined differences in depressive symptoms, quality of life, and fluid compliance based on the timing of the intervention (first or after 90-day waitlist). In both phases, participants who received CBT experienced significantly greater benefits across outcomes. Findings suggest a sequence effect for depressive symptom reduction (greater benefit for first group versus waitlist), but none for quality of life or fluid compliance (see Table 7 and 8, and Appendix E for more detail).^69^