# METHODS

## TOPIC DEVELOPMENT

This topic was nominated by Dr. Susan Crowley, VHA National Program Director for Kidney Disease and Dialysis. The scope was refined through a process that included a preliminary review of published peer-reviewed literature and consultations with our operational partners and a technical expert panel (TEP). Our approach was guided by a conceptual framework developed in consultation with our operational partners and TEP (Figure 1).

The Key Questions (KQs) for this systematic review were:

KQ1 What are the performance characteristics of screening tools for depression in patients with ESRD?
KQ2 What is the impact of screening for depression in patients with ESRD on intermediate and/or patient outcomes?
KQ3 What is the effectiveness of depression treatment in patients with ESRD and depression?
  a. pharmacological treatment
  b. non-pharmacological treatment
  c. pharmacological and non-pharmacological treatments combined
KQ4 In patients with ESRD and depression, what are the potential harms of:
  a. screening?
  b. treatment?
    i. pharmacological
    ii. non-pharmacological
KQ5 Do the benefits or harms of screening differ by:
  a. patient characteristics or other social determinants of health?
  b. setting?
  c. screening characteristics/process?
  d. other (eg, patient engagement/receptivity to treatment, social support)?
  e. timing and type of follow up?
KQ6 Do the benefits or harms of treatment differ by:
  a. patient characteristics or other social determinants of health?
  b. setting?
  c. provider characteristics (eg, mental health, primary care provider [PCP], other)?
  d. other (eg, patient engagement/receptivity to treatment, social support)?
  e. timing and type of follow up?

Figure 1 Analytic Framework

Note. Associated key questions are noted in the shaded circles.

## SEARCH STRATEGY

Search strategies were developed in consultation with a research librarian and were peer reviewed by a second research librarian using the instrument for Peer Review of Search Strategies (PRESS).^14^ We conducted a review of the literature by systematically searching, reviewing, and analyzing the scientific evidence as it pertains to the research questions. To identify relevant trials, we searched Ovid MEDLINE, PsycINFO, Elsevier EMBASE, and Ovid EBM Reviews Cochrane Database of Systematic Reviews (CDSR, DARE, HTA, Cochrane CENTRAL, etc). We searched all available years of publication from database inception (1946 for Ovid MEDLINE®) through April 2019. We reviewed the bibliographies of relevant articles and contacted experts to identify additional studies. To identify in-progress or unpublished studies, we searched the VHA HSR&D website, ClinicalTrials.gov, and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP).

## STUDY SELECTION

Criteria for population, interventions, comparators, outcomes, timing, and setting (PICOTS) were developed in collaboration with our operational partners and TEP (see Table 1). Based on pre-specified criteria, 80% of titles and abstracts were reviewed manually by 2 reviewers, and the remaining 20% were reviewed by at least 2 reviewers using Abstrackr, a web-based abstract screening tool.^15^ Two reviewers then independently assessed the full text of included citations for final inclusion. All discordant results were resolved through consensus or consultation with a third reviewer. Articles meeting eligibility criteria were included for data abstraction.

We included diagnostic accuracy studies of depression tools for patients with ESRD. We also included randomized and non-randomized controlled trials, and observational studies of patients with ESRD and comorbid depression (defined by established thresholds for chronically ill populations)^16–20^ that directly compared pharmacological and non-pharmacological interventions to each other, placebo, or waitlist control. We excluded studies examining patients with acute kidney injury (AKI), or with CKD stages 1-4. To examine the impact of screening and effectiveness of treatment for depression in patients with ESRD (KQs 2 and 3) we included only randomized and non-randomized controlled trials. Citation lists of included systematic reviews were reviewed for relevant studies. For each key question of interest, we used a “best evidence” approach to guide additional study design criteria depending on the question under consideration and the literature available (see Table 1 and Appendix B).^21^

Table 1 PICOTS by Key Question

Key Question: | KQ1: What are the performance characteristics of screening tools for depression in patients with ESRD? | KQ2: What is the impact of screening for depression in patients with ESRD on intermediate and/or patient outcomes? | KQ3: What is the effectiveness of depression treatment in patients with ESRD and depression:; a. pharmacological?; b. non-pharmacological?; c. pharmacological and non-pharmacological treatments combined | KQ4: In patients with ESRD, what are the potential harms of:; a. screening?; b. treatment for depressed patients?; i. Pharmacological?; ii. non-pharmaco-logical? | KQ5: Do the benefits or harms of screening differ by:; a. patient characteristics or other social determinants of health?; b. setting?; c. screening characteristics/process?; d. other (eg, patient engagement/receptivity to treatment, social support)?; e. timing and type of follow up? | KQ6: Do the benefits or harms of treatment differ by:; a. patient characteristics or other social determinants of health?; b. setting?; c. provider characteristics (eg, mental health, PCP)?; d. other (eg, patient engagement/receptivity to treatment, social support)?; e. timing and type of follow up?
Population | Adults with ESRD | Adults with ESRD | Adults with ESRD and depression (Cutoffs: PHQ-9 ≥ 10;^16^ CES-D ≥ 18;^17^ HAM-D ≥ 12;^18^ BDI-II ≥ 16;^17,18^ BDI ≥ 13;^18^ HADS ≥ 8^19,20^) | | a. Adults with ESRD; b. Adults with ESRD and depression (Cutoffs: PHQ-9 ≥ 10;^16^ CES-D ≥ 18;^17^ HAM-D ≥ 12;^18^ BDI-II ≥ 16;^17,18^ BDI ≥ 13;^18^ HADS ≥ 8^19,20^) | Adults with ESRD
Intervention | Depression screening | | Pharmacological and non-pharmacological treatments for depression | Depression screening, and pharmacological and non-pharmacological treatments for depression | Depression screening | Pharmacological and non-pharmacological treatments for depression
Comparators | Clinical evaluation, Other screening tools. Exclude DSM-III and earlier | No screening, other screening tool | Placebo, waitlist control, other intervention | a. No screening, other screening tool; b. Placebo, waitlist control, other intervention | No screening, other screening tool | Placebo, waitlist control, other intervention
Outcomes | [underlined: Diagnostic test performance:] sensitivity, specificity, positive predictive value, and negative predictive value | [underlined: Therapeutic impact:] timing, setting, or type of treatment.; [underlined: Intermediate and Patient outcomes:] depressive symptoms, mortality, suicide attempts or completion, hospitalization, ED/urgent care utilization, patient satisfaction, adherence to dialysis, medication, or treatment, pain medication reduction, BP/metabolic control, quality of life, other outcomes (eg, employment) | [underlined: Intermediate and Patient outcomes:] depressive symptoms, mortality, suicide attempts or completion, hospitalization, ED/urgent care utilization, patient satisfaction, adherence to dialysis, medication, or treatment, pain medication reduction, BP/metabolic control, quality of life, other outcomes (eg, employment) | Adverse effects or unintended consequences | [underlined: Intermediate and Patient outcomes:] depressive symptoms, mortality, suicide attempts or completion, hospitalization, ED/urgent care utilization, patient satisfaction, adherence to dialysis, medication, or treatment, pain medication reduction, BP/metabolic control, quality of life, other outcomes (eg, employment)
Timing | Any
Settings | All settings in US or international (VHA, hospital community, community mental health, ED, urgent care, other community)
Study design | Systematic reviews, RCTs, NRCTs, Observational studies | Systematic reviews, RCTs, NRCTs | | Systematic reviews, RCTs, NRCTs, Observational studies

Note. Subpopulations may include: Patient demographic characteristics or social determinants of health; ESRD subgroup (w/o treatment; treated by kidney transplant; treated by HD (home or clinic); treated by PD (home or clinic); clinical severity (ESRD or depression); setting (eg VHA, community hospitals, community mental health, ED, urgent care visits for mental health, home vs clinic-based dialysis); other.

Abbreviations: CES-D = Center for Epidemiologic Studies Depression Scale; BDI = Beck Depression Inventory; BP = blood pressure; ED = emergency department; ESRD = End-stage Renal Disease; HADS = Hospital Anxiety and Depression Scale; HAM-D = Hamilton Depression Rating Scale; NRCT = Non-randomized controlled trial; PHQ-9 = Patient Health Questionnaire-9; RCT = Randomized controlled trial; VHA = Veterans Health Administration

## DATA ABSTRACTION

Data from studies meeting inclusion criteria were abstracted by 1 investigator and confirmed by at least 1 additional reviewer. From each study, we abstracted the following where available: study design, sample size, setting, population characteristics, subject inclusion and exclusion criteria, the study and comparator interventions including details related to the dosage, setting, timing, and administration of screening and interventions, duration of treatment, duration of follow-up, intermediate and health outcomes, and relevant harms.

## QUALITY ASSESSMENT

Two reviewers independently assessed the methodological quality of each study using established methods for each study design. For trials, we used criteria established by the US Preventive Services Taskforce and adapted for depression interventions.^22–24^ We supplemented this with the Revised Tool for the Quality Assessment of Diagnostic Accuracy Studies QUADAS-2^25^ and the Newcastle-Ottawa Scale^26^ for diagnostic accuracy and observational studies respectively (see Appendices C and D). Disagreements were resolved by consensus or a third reviewer.

## DATA SYNTHESIS

We qualitatively synthesized the evidence for all key questions and presented the findings in tables. For Key Question 1, we categorized assessment tools as a) screening for MDD, and b) screening for a wider range, from subclinical depressive symptoms to MDD. In addition, we present detailed findings for studies comparing a screening tool to a gold standard clinical interview, and provide a summary of studies that use another tool as a reference standard (eg, BDI-II).^27^ We were unable to quantitatively synthesize the evidence because studies were not clinically heterogenous and/or of the same intervention and outcome measure.^28^

## RATING THE BODY OF EVIDENCE

We assessed the overall strength of evidence (SOE) for outcomes using a method developed for the Agency for Healthcare Research and Quality’s (AHRQ) Evidence-based Practice Centers (EPCs).^29^ The AHRQ EPC method considers study limitations, directness, consistency, precision, and reporting bias to classify the strength of evidence for individual outcomes independently for randomized controlled trials (RCTs) and observational studies, with supplemental domains of dose-response association, plausible confounding that would decrease the observed effect, and strength of association, as well as separate guidance for applicability.^30^ Ratings will be based on the following criteria:

- High: Very confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has few or no deficiencies, the findings are stable, and another study would not change the conclusions.
- Moderate: Moderately confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has some deficiencies and the findings are likely to be stable, but some doubt remains.
- Low: Limited confidence that the estimate of effect lies close to the true effect for this outcome. The body of evidence has major or numerous deficiencies (or both). Additional evidence is needed before concluding either that the findings are stable or that the estimate of effect is close to the true effect.
- Insufficient: No evidence, unable to estimate an effect, or no confidence in the estimate of effect for this outcome. No evidence is available, or the body of evidence has unacceptable deficiencies, precluding reaching a conclusion.