# INTRODUCTION

The incidence and prevalence of end-stage renal disease (ESRD) in the United States (US) have increased steadily over the past 4 decades.^1^ Veterans experience a higher burden of chronic kidney disease (CKD) and ESRD than the population at large.^2^ Roughly 13,000 Veterans initiate dialysis annually, making up nearly 11% of all cases in the US.^2^

Patients with ESRD experience major depressive disorder (MDD) at 3 to more than 6 times that of the general US population, depending on the method of assessment.^3,4^ Comorbid depression is associated with treatment noncompliance, poorer quality of life, worse sleep, increased emergency department (ED) visits, hospitalizations, suicide, and all-cause mortality.^5–8^

Veterans experience MDD at more than twice the rate of the general US population (7.1% vs 13.5%).^3,9^ According to United States Renal Data System (USRDS) data, rates of depression in Veterans with ESRD increased steadily between 2007 and 2015, with recent data indicating prevalence rates of 33%.^10^

In the Veterans Health Administration (VHA), some Veterans with ESRD receive kidney care entirely within the VHA. However, due to space limitations and variation in dialysis care available across VHA settings (inpatient, outpatient, or none), a large percentage of Veterans are referred to dialysis units in the community.

The Centers for Medicare and Medicaid Services’ (CMS) inclusion of depression screening for ESRD patients as part of their pay-for-performance (P4P) Quality Incentive Program (QIP) requires routine depression screening for patients with ESRD.^11^ However, due to the lack of system-wide screening tool requirements, there is wide variation in the tools used to initially screen for depression, as well as for follow-up after a positive initial screen (ranging from the Patient Health Questionnaire 2 [PHQ-2] to the Center for Epidemiologic Studies Depression Scale [CES-D], and the Beck Depression Inventory [BDI-II], to a clinical interview). In addition, the implementation of depression screening likely varies widely by site, potentially ranging from the PHQ-2 included on written intake forms or verbal assessment in a waiting room, to a confidential interview with a licensed clinician. Follow-up to a positive screen also varies widely, and Veterans with ESRD and comorbid depression may be referred to mental health providers within the VHA, or to community hospitals and mental health settings.

Currently, there are no established guidelines for the treatment of depression in patients with ESRD. Roughly 30% of Veterans receive an antidepressant during the ESRD post-transition phase.^10^ Efficacy studies are limited, however, and the evidence is unclear.^12^ Psychosocial treatments and Cognitive Behavioral Therapy (CBT) are also commonly used; however, interventions vary widely, and the evidence is limited.^13^

Given the wide variation in depression screening and treatment options for Veterans with ESRD, an understanding of the validity of screening tools used in both VHA and community settings, and the subsequent depression treatment-related outcomes for Veterans in all US healthcare settings, is vital.

The purpose of this review is to identify depression screening tools (and/or thresholds) appropriate for Veterans with ESRD, and to better understand the impact, benefits, and harms of depression screening and subsequent treatment for depression in Veterans (and Veteran subpopulations) with ESRD.