# EXECUTIVE SUMMARY

## AIM

We conducted a systematic review to evaluate the performance characteristics of screening tools for depression in Veterans with end-stage renal disease (ESRD), and to better understand the impact, benefits, and harms of depression screening and subsequent treatment for depression.

## METHODS

We conducted a systematic review by searching electronic databases, clinical trial registries, and reference lists from database inception through April 2019 for diagnostic accuracy studies of depression tools for patients with ESRD and for randomized and non-randomized controlled trials directly comparing pharmacological and non-pharmacological interventions for depression in ESRD patients to each other, placebo, or waitlist control. We abstracted data on study design, interventions, and outcomes. Dual assessment of studies’ full text, quality, and strength of evidence (SOE) was agreed upon by consensus using pre-specified criteria.

## RESULTS

We included 20 treatment randomized controlled trials (RCT)s and 16 diagnostic accuracy studies.

### Key Question 1 What are the performance characteristics of screening tools for depression in patients with ESRD?

For diagnostic accuracy, the best studied tool was the Beck Depression Inventory-II (BDI-II). Table i uses data from the 2 United States (US) and 2 United Kingdom (UK) studies that screened for major depressive disorder (MDD) to compare positive and negative predictive values across reported MDD prevalence rates for a) the general US population (7.1%); b) Veterans receiving care in Veterans Health Administration (VHA) patient-centered medical homes (13.5%); c) patients with ESRD, diagnosed using a gold standard clinical interview (22.8%); d) Veterans with ESRD (method of diagnosis not-reported; 33%), and e) patients with ESRD, diagnosed using a screening tool (39.3%). Studies evaluate both the BDI-II and the Patient Health Questionnaire-9 (PHQ-9) and highlight the impact of the population-specific prevalence rate on positive and negative predictive values for a specific threshold. It is important to note that at the higher prevalence rates seen in patients with ESRD, negative predictive value is generally high. However, positive predictive value is often less than ideal (due to the higher rate of false positives), and providers should keep this in mind if using the results of depression screening tools to guide treatment decisions.

Across the 4 BDI-II studies, a cutoff of ≥16 provides the best balance between sensitivity and specificity. In fact, we found that in some studies, the BDI-II performed reasonably well when compared to a gold standard clinical interview. The caveats, however, are that very few studies included participants that resemble US Veterans, there was heterogeneity across studies in the way the tools were administered, and very few studies contributed data for the same thresholds.

Table i Positive and negative predictive values associated with depression rates in 4 US populations

Author, Year N, % MDD (Ref), % MDD Tool, Cutoff | Sensitivity (%) | Specificity (%) | Prevalence Assumption (%) | Positive Predictive Value | Negative Predictive Value
Beck Depression Inventory-II (BDI-II)
Balogun, 2011; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 7.1^a^ | 0.88 | 0.50
Balogun, 2011; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 13.5^b^ | 0.32 | 0.94
Balogun, 2011; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 22.8^c^ | 0.47 | 0.89
Balogun, 2011; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 33.0^d^ | 0.59 | 0.83
Balogun, 2011; N = 96; 30.6%, 37.1%; BDI ≥10 | 68 | 77 | 39.3^e^ | 0.66 | 0.79
Watnick, 2005; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 7.1^a^ | 0.33 | 0.99
Watnick, 2005; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 13.5^b^ | 0.50 | 0.98
Watnick, 2005; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 22.8^c^ | 0.66 | 0.97
Watnick, 2005; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 33.0^d^ | 0.76 | 0.95
Watnick, 2005; N = 62; 19.4%, NR; BDI ≥16 | 91 | 86 | 39.3^e^ | 0.81 | 0.94
Chilcot, 2008; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 7.1^a^ | 0.35 | 0.99
Chilcot, 2008; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 13.5^b^ | 0.52 | 0.98
Chilcot, 2008; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 22.8^c^ | 0.67 | 0.96
Chilcot, 2008; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 33.0^d^ | 0.77 | 0.94
Chilcot, 2008; N = 40; 22.5%; 30-32.5%; BDI ≥16 | 88.9 | 87.1 | 39.3^e^ | 0.82 | 0.92
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 7.1^a^ | 0.26 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 13.5^b^ | 0.42 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 22.8^c^ | 0.57 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 33.0^d^ | 0.69 | 1.0
Grant, 2008; N = 57; 12.3%; 31.6%; BD I≥15 | 100 | 78 | 39.3^e^ | 0.74 | 1.0
Patient Health Questionnaire 9 (PHQ-9)
Watnick, 2005; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 7.1^a^ | 0.47 | 0.99
Watnick, 2005; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 13.5^b^ | 0.64 | 0.99
Watnick, 2005; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 22.8^c^ | 0.77 | 0.97
Watnick, 2005; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 33.0^d^ | 0.85 | 0.96
Watnick, 2005; N = 62; 19.4%, NR; PHQ-9≥10 | 92 | 92 | 39.3^e^ | 0.88 | 0.95

a General US population,

b Veterans receiving care in VHA patient-centered medical homes,

c Patients with ESRD, diagnosed using a gold standard clinical interview,

d Veterans with ESRD (diagnosis method NR),

e Patients with ESRD, diagnosed using a screening tool.

Abbreviations: BDI-II = Beck Depression Inventory-II; MDD = Major Depressive Disorder

Studies evaluating a (typically short) screening tool against an established validated tool performed well overall. Since the Quality Incentive Program (QIP) requires a follow-up assessment after an initial positive screen, these short tools may be good options for this purpose. The BDI-Fast Screen (FS) in particular performed well when compared to the BDI-II.

### Key Question 2 What is the impact of screening for depression in patients with ESRD on intermediate and/or patient outcomes?

We identified no studies examining the impact of screening on intermediate or health outcomes.

### Key Question 3 What is the effectiveness of depression treatment in patients with ESRD and depression?

Among pharmacological interventions SSRIs were the most-studied drug class, and the evidence was largely insufficient, except for low-strength evidence from 1 trial of sertraline that it improves clinician-rated depression more than cognitive behavioral therapy (CBT). We found moderate SOE that long-term, high-dose Vitamin D3 is ineffective for reducing depression severity. For non-pharmacological treatments we found low SOE that CBT is more effective than other forms of psychotherapy and placebo for depression improvement and quality of life. There was also low SOE for acupressure reducing depression severity when compared with usual treatment or sham acupressure (see Table ii). Evidence on all other treatments was insufficient to draw conclusions.

Table ii Strength of evidence of intervention effectiveness

Intervention | N | Depression Severity | Quality of Life | Fatigue | Sleep Quality
SSRI vs control | 94 | Insufficient | -- | -- | --
Citalopram vs psychological training | 44 | Insufficient | -- | -- | --
Sertraline vs CBT | 120 | No Difference | -- | -- | --
CBTvs psychotherapy | 90 | Benefit | Benefit | -- | --
CBTvs psychoeducation | 130 | Insufficient | -- | -- | --
CBT vs control | 125 | Benefit | Benefit | -- | --
MBSR vs TAU | 41 | Insufficient | -- | -- | --
Guided Imagery vs control | 80 | Insufficient | -- | -- | --
Benson Relaxation Technique vs. control | 70 | Insufficient | -- | -- | --
Latihan Pasrah Diri vs control | 36 | Insufficient | Insufficient | -- | --
Hope Therapy vs active control | 50 | Insufficient | -- | -- | --
Quran vs TAU | 60 | Insufficient | -- | -- | --
Exercise training vs. control | 50 | Insufficient | -- | -- | --
Acupressure vs TAU | 204 | Benefit | -- | Insufficient | Insufficient
Acupressure vs sham | 96 | Benefit | -- | -- | --
Acupressure vs TEAS | 108 | Insufficient | -- | Insufficient | Insufficient
High dose Vitamin C vs placebo | 746 | No Difference | -- | -- | --
Omega 3 Fatty Acids vs placebo | 54 | Insufficient | -- | -- | --

Note. Colors represent the Strength of Evidence: Gray = Insufficient evidence; yellow = low SOE; blue = moderate SOE

Abbreviations: CBT = cognitive behavioral therapy; MBSR = mindfulness-based stress reduction; SSRI = selective serotonin reuptake inhibitor; TAU = treatment as usual; TEAS = transcutaneous electrical acupoint stimulation.

### Key Question 4 In patients with ESRD and depression, what are the potential harms of screening and treatment?

Five pharmacological trials reported adverse events. In trials of sertraline, withdrawal due to AEs and nausea were more frequently in participants who received sertraline versus placebo. However, frequency and severity were similar to the general population. Withdrawals due to AEs were also reported in a study of high-dose Vitamin D3.

### Key Question 5 Do the benefits or harms of screening differ by subpopulations?

One study compared the BDI-II administered on- versus off-dialysis. Agreement was generally high, particularly among depressed participants. However, among non-depressed participants, somatic symptom scores and overall BDI-II scores were higher when assessed on dialysis.

### Key Question 6 Do the benefits or harms of treatment differ by subpopulations?

Three trials examined differences in the benefits or harms of interventions for the treatment of depression in patients with ESRD by subpopulation. Findings suggest no difference in the effect of high-dose Vitamin D3 or omega-3 fatty acids by demographic characteristics. Participants with vascular depression receiving high-dose Vitamin D3 reported significantly greater symptom reduction than those with MDD. Finally, among participants receiving CBT, symptom reduction was greater for those who received the intervention immediately versus the waitlist control.

## CONCLUSION

There is limited research evaluating the diagnostic accuracy of most screening tools for depression in patients with ESRD, and the existing studies may not be generalizable to patients in the US and Veterans receiving care in VHA settings. Screening and intervention studies suffer from limitations related to methodological quality or reporting. In adults with ESRD, the BDI-II with a cutoff of ≥16 provides a good balance of sensitivity and specificity. More research is needed to support the use of other tools. We found low-strength evidence that sertraline and CBT provide benefit for depressive symptoms, and do not differ significantly from each other. There is low-strength evidence that CBT is more effective than psychotherapy or placebo for depressive symptoms and quality of life, low-strength evidence that acupressure is more effective for reducing depression than sham or usual care, and moderate-strength evidence that high dose vitamin D3 is ineffective. Although our ability to form conclusions about the effectiveness of interventions for depression in patients with ESRD is limited, it is important to note that across studies within-group improvements were common, despite insignificant differences between groups, suggesting that treatment generally may be better than no treatment in this population. More research is needed.

## ABBREVIATIONS TABLE

Abbreviation: Term
AE: Adverse event
AKI: Acute kidney injury
BDI: Beck Depression Inventory
BDI-II: Beck Depression Inventory-II
BDI-FS: Beck Depression Inventory-Fast Screen
BP: Blood pressure
BRT: Benson Relaxation Technique
CA: California
CBT: Cognitive Behavioral Therapy
CDI: Cognitive Depression Index
CDSR: Cochrane Database of Systematic Reviews
CES-D: Center for Epidemiologic Studies Depression Scale
CI: Confidence interval
CKD: Chronic Kidney Disease
CMS: Centers for Medicare and Medicaid Services
COPD: Chronic Obstructive Pulmonary Disease
CVD: Cardiovascular disease
DASS: Depression, Anxiety, and Stress Scale
DBP: Diastolic blood pressure
DI-MHD: Depression Inventory – Maintenance Hemodialysis
DM: Diabetes Mellitus
EBM: Evidence-based Medicine
ED: Emergency department
EPC: Evidence-based Practice Center
ESAS: Edmonton Symptom Assessment Scale
ESP: Evidence Synthesis Program
ESRD: End-stage Renal Disease
ET: Exercise training
FLU: Fluoxetine
GDS-15: Geriatric Depression Scale-15
HADS: Hospital Anxiety and Depression Scale
Ham-D: Hamilton Depression Rating Scale
HD: Hemodialysis
HR: Heartrate
HRV: Heartrate variability
HS: High school
ICD-10: International Statistical Classification of Diseases and Related Health Problems-10
KDQOL-SF 36: Kidney Disease Quality of Life-Short Form 36
KQ: Key Question
LPD: Latihan Pasrah Diri
MA: Meta-analysis
MADRS: Montgomery–Åsberg Depression Rating Scale
MAOI: Monoamine oxidase inhibitor
MBSR: Mindfulness-based Stress Reduction
MD: Mean difference
MDD: Major depressive disorder
MHI5: Mental Health Inventory 5
MINI: Mini International Neuropsychiatric Interview
MMSE: Mini-Mental Status Examination
MX: Mexico
NM: New Mexico
NR: Not reported
NRCT: Non-randomized controlled trial
NS: Not significant
NY: New York
OPCC&CT: Office of Patient Centered Care and Cultural Transformation
OR: Oregon
P: P-value
P4P: Pay-for-performance
PBO: Placebo
PCP: Primary care provider
PD: Peritoneal dialysis
PFS: Piper Fatigue Scale
PHQ-9: Patient Health Questionnaire-9
PICOTS: Population, interventions, comparators, outcomes, timing, setting, and study design
PLC: Profile of Quality of Life in the Chronically Ill
PSE: Psychoeducation
PSQI: Pittsburgh Sleep Quality Index
pts: Participants
QIDS-C: Quick Inventory of Depressive Symptomatology - Clinician
QIP: Quality Incentive Program
QOL: Quality of Life
QUADAS: Tool for the Quality Assessment of Diagnostic Accuracy Studies
RCT: Randomized controlled trial
RR: Relative risk
SAE: Serious adverse event
SBP: Systolic blood pressure
SCID-I: The Structured Clinical Interview for DSM-IV Axis I Disorders
SE: Standard error
SERT: Sertraline
SMD: Standard mean difference
SOE: Strength of evidence
SR: Systematic review
SRQ: Self-Reporting Questionnaire
SSRI: Selective serotonin reuptake inhibitor
TAU: Treatment as usual
TEAS: Transcutaneous Electrical Acupoint Stimulation
TEP: Technical expert panel
TX: Texas
UK: United Kingdom
US: United States
VA: Veterans Affairs
VHA: Veterans Health Administration
WA: Washington