# APPENDIX F PEER REVIEW COMMENTS/AUTHOR RESPONSES

Reviewer Number | Reviewer Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
2 | Yes | Thank you.
3 | Yes | Thank you.
5 | Yes | Thank you.
6 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
2 | No | Thank you.
3 | No | Thank you.
5 | No | Thank you.
6 | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
2 | No | Thank you.
3 | No | Thank you.
5 | No | Thank you.
6 | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
3 | Minor: Amend page “iv” of Table of Contents (line 59) to include; KQ3: Effectiveness of Depression Treatment in Patients with ESRD and Depression | Thank you. We have resolved this omission.
5 | This report is thorough, and unfortunately comprehensive. I say ‘unfortunately comprehensive’ because this highlights the lack of research in the area.; I think it is critical for the VA to fund studies to consider not only screening and treatment, but also the potential sequelae and resources available to address a large number of positive screening tests. This work is not to be underestimated, as tremendous resources would need to be employed at local facilities where screening may occur, given the high rates of depressive symptoms in patients on dialysis. | Thank you.
5 | I have now read through the entire report, but do not have time today to write more extensively on the details within the report.; I would urge the team to include more details about treatment in the executive summary. A table about screening is including in that initial summary. I think it would serve the future readers well to have a similar summary of the findings on treatment in this population. Most readers will not have time to review the entire 80+ page report. | Thank you. We have added a table to both the executive summary and the discussion.
5 | Page 1, line 2 ‘tools’ not ‘tool’. | Thank you, corrected.
5 | Page 6, line 14 ‘United States’ not ‘United State’. | Thank you, corrected.
6 | Overall, I think that this VA ESP systematic review is very comprehensive and organized. It will be an invaluable report and resource for VA. Congratulations to the team. | Thank you.
6 | 1. executive summary (p.1, line 2). It should be tools and not tool | Thank you, corrected.
6 | 2. executive summary (p.1, line 6). I would provide also the start date for the electronic database search | Thank you, revised.
6 | 3. executive summary, results. I would consider reorganizing the results with subcategories for each question - KQ1 to KQ6. Since this is a summary, many readers will not review the remainder of the document and will be unaware of the items addressed. Therefore, I think it is important to include each question and the results for each. Currently, KQ2, KQ4, and KQ5 are not addressed in this section. | Thank you, revised.
6 | 4. Throughout the report, kidney is preferred to be used instead of renal | We have replaced renal with kidney in cases that aren’t proper nouns, diagnoses, etc. (eg, we replaced renal failure with kidney failure).
6 | 5. p. 8 - I could not understand what the circles with number are referring to. Please elaborate | Thank you. We have added a footnote: “Note. Associated key questions are noted in the shaded circles.”
6 | 6. p. 9 - the comparators row should be revised b/c no screening or other screening tool is not the comparator for all of the studies for the questions | Thank you! Revised.
6 | 7. p. 13 - please footnote and provide definitions for patient selection, index test, reference test, and flow and timing | Thank you. We added a footnote referencing Appendix C.
6 | 8. Table 2 - under the column “study setting sample characteristics and demographics” - please list the characteristics/criteria throughout and report as NR if not reported. This provides a better sense of what was missing | Thank you. Edited.
6 | 9. Page 28 - as above, the lack of studies addressing KQ2 is significant and should be reported in the executive summary. Please also state here whether there are any ongoing studies addressing this topic. | Thank you. We added this to the executive summary. We did not identify any ongoing studies addressing this topic. Our database search includes PubMed, in which ClinicalTrials.gov trials are indexed.
6 | 10. Table 8 - please footnote and define “quality” - how it was determined and the criteria used to make such determination. I think you could cite appendix C and D | Thank you. We have added a reference to Appendix D in the footer.
6 | 11. Table 9 - please footnote and define meaning of “k” that is included throughout the table | Thank you, we have added definitions for both k and n to the footer.
6 | 12. Table 9 - please footnote and define “strength of evidence” - how it was determined and the criteria used to make such determination. | Thank you. This information is in the footer. We have reorganized it for clarity.
6 | 13. p. 51 - if available, would list frequencies of adverse events | Thank you. We have added a table to with reported AE frequencies to the appendix.
6 | 14. Discussion. P. 53 - as with the executive summary, I would consider organizing the discussion around the KQs so that when one reads the summary, they are aware of all of the domains addressed. | Thank you, to insure all key questions are addressed in the discussion, we have added a statement that there were no studies found examining outcomes related to screening.
6 | 15. Discussion, p. 53 - I would elaborate upon how the populations studies bear little resemblance to Veterans. Is it differences in age, race, SES, etc? Also, how might this limit generalizability of the findings from studies? | Thank you, we have updated this section.
6 | 16. Discussion, p. 53, line 30. “positive predictive value is less than ideal” - please elaborate on what is considered “ideal” | Thank you. We clarified this.
6 | 17. Discussion, p. 54, line 24. would give an example of a short screening tool | Thank you. The next sentence in that paragraph provides an example (ie, BDI-FS).
6 | 18. Discussion. I would elaborate on the difference between quality of evidence and strength of evidence. | Thank you. We did not distinguish these differences in the discussion. However, these concepts are described in detail in Methods and Appendices.
6 | 19. p. 55, line 3 - spell out “ROB” | Thank you, edited.
6 | 20. I would consider including in “research gaps/future research” section the opportunity to explore the unaddressed questions (e.g,, KQ2, etc.) | Thank you. We have edited this section.