# APPENDIX E ADVERSE EVENTS REPORTED IN DEPRESSION TREATMENT TRIALS IN PATIENTS WITH END-STAGE RENAL DISEASE

Severity | System | Adverse Event | Blumenfield, 1997^60^ | | Friedli, 2017^61,*^ | | Mehrotra, 2019^63^ | | Taraz, 2013^62^,^†^
Severity | System | Adverse Event | Fluoxetine (N = 6) | Placebo (N = 7) | Sertraline (N = 15) | Placebo (N = 15) | CBT (N = 60) | Sertraline (N = 60) | Sertraline (N = 21) | Placebo (N = 22)
Non-Serious | Autonomic | Dry mouth | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Cardiovascular | Cardiac unspecified | --- | --- | --- | --- | 3 | 9 | --- | ---
Non-Serious | Cardiovascular | Hypotension | 4 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Cardiovascular | Palpitations | --- | --- | 1 | 0^*^ | --- | --- | --- | ---
Non-Serious | Gastrointestinal | Abdominal pain | 1 | 2 | --- | --- | --- | --- | --- | ---
Non-Serious | Gastrointestinal | Constipation | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Gastrointestinal | Diarrhea | 1 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Gastrointestinal | Dyspepsia | 1 | 0 | --- | --- | --- | --- | 6 | 4
Non-Serious | Gastrointestinal | Gastro-enteritis | 0 | 2 | --- | --- | --- | --- | --- | ---
Non-Serious | Gastrointestinal | Gastrointestinal unspecified | --- | --- | --- | --- | 11 | 22 | --- | ---
Non-Serious | Gastrointestinal | Nausea | 5 | 2 | 1 | 0^*^ | --- | --- | 7 | 3
Non-Serious | Gastrointestinal | Vomiting | 3 | 3 | --- | --- | --- | --- | --- | ---
Non-Serious | Musculoskeletal | Myalgia | 1 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Neurological | Dizziness | 1 | 0 | 1 | 0^*^ | --- | --- | 5 | 3
Non-Serious | Neurological | Headache | 3 | 0 | 1 | 0^*^ | --- | --- | 4 | 2
Non-Serious | Neurological | Insomnia | 2 | 1 | 1 | 0^*^ | --- | --- | --- | ---
Non-Serious | Neurological | Nervous system unspecified | --- | --- | --- | --- | 0 | 8 | --- | ---
Non-Serious | Neurological | Sensation disturbance | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Neurological | Tremors | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Psychiatric | Abnormal thought | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Psychiatric | Anorexia | --- | --- | --- | --- | --- | --- | 2 | 4
Non-Serious | Psychiatric | Anxiety | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Psychiatric | Nervousness | 1 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Bronchitis | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Cough | 0 | 2 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Dyspnea | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Pharyngitis | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Rhinitis | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Respiratory | Upper respiratory tract infection | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Skin | Furunculosis | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Skin | Pruritus | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Skin | Skin ulcer | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Skin | Sweating | --- | --- | 1 | 0^*^ | --- | --- | --- | ---
Non-Serious | Other | Dehydration | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Other | Edema | 0 | 1 | --- | --- | --- | --- | --- | ---
Non-Serious | Other | Flu syndrome | 1 | 0 | --- | --- | --- | --- | --- | ---
Non-Serious | Other | Hair Loss | --- | --- | --- | --- | --- | --- | 1 | 1
Non-Serious | Other | Other unspecified | --- | --- | --- | --- | 3 | 17 | --- | ---
Non-Serious | Other | Sexual dysfunction | --- | --- | --- | --- | --- | --- | 2 | 1
Non-Serious | Other | Tooth infection | 1 | 0 | --- | --- | --- | --- | --- | ---
Serious | Gastrointestinal | Gastrointestinal unspecified | --- | --- | --- | --- | 1 | 1 | --- | ---
Serious | Cardiovascular | Cardiac unspecified | --- | --- | --- | --- | 4 | 4 | --- | ---
Serious | Other | Death | --- | --- | 1 | 0 | 2 | 0 | --- | ---
Serious | Other | Major bleeding | --- | --- | --- | --- | 1 | 2 | --- | ---
Serious | Other | Other unspecified | --- | --- | --- | --- | 2 | 9 | --- | ---

* The events reported in this table are only those that resulted in study dropout. There were other adverse events reported narratively, but it was not clear from the text which category or study arm they occurred in, so they are not recorded in this table.

† It is unclear whether the events of study dropouts were included in these totals. There was 1 death in each group and some attrition due to AEs, but the dropouts were not analyzed in this per-protocol study.