# APPENDIX D QUALITY AND APPLICABILITY ASSESSMENT OF RANDOMIZED CONTROLLED TRIALS

Author, Year | Rating Criteria^*^ | | | | | | | | | | | | | | | | | Funding source | Overall Quality Rating | Applicability
Author, Year | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 10 | 11 | 12 | 13 | 14 | 15 | 16 | 17 | Funding source | Overall Quality Rating | Applicability
Al Saraireh, 2018^68^ | Y | NR | N | NA | Y | U | U | N | Y | N | Y | N | Y | U | Y | NA | N | Investigator | Poor | Fair
Babamohamadi, 2017^79^ | NR | NR | N | U | Y | U | U | N | Y | N | U | N | Y | Y | U | U | N | NR | Poor | Poor
Beizaee, 2018^75^ | Y | Y | Y | Y | Y | Y | Y | N | Y | N | Y | N | N | U | Y | NA | Y | University | Fair | Fair
Blumenfield, 1997^60^ | NR | Y | U | U | N | U | Y | Y | Y | N | N | N | Y | U | Y | N | N | Industry grant | Poor | Fair
Cukor, 2014^69^ | NR | NR | Y | U | Y | Y | Y | Y | Y | N | N | Y | Y | U | Y | N | N | NIDDK | Fair | Fair
Duarte, 2009^67^ | Y | Y | N | U | Y | Y | Y | Y | Y | N | N | Y | Y | Y | Y | N | N | Government | Fair | Fair
Friedli, 2017^61^ | Y | Y | Y | N | Y | Y | Y | Y | Y | Y | N | N | Y | U | Y | N | N | NIH grant | Fair | Good
Gharekhani, 2014^66^ | Y | U | Y | N | Y | N | N | Y | Y | Y | N | N | Y | Y | Y | N | N | University | Poor | Good
Heshmatifar, 2015^73^ | NR | NR | Y | U | Y | U | U | N | Y | N | N | Y | Y | U | U | N | U | NR | Poor | Fair
Hosseini, 2012^64^ | U | NR | Y | Y | Y | U | U | N | Y | N | N | Y | Y | U | Y | N | N | Government | Poor | Fair
Kalani, 2019^71^ | N | U | Y | U | Y | U | U | U | Y | U | Y | N | Y | Y | Y | U | N | University | Poor | Fair
Kouidi, 2010^74^ | NR | NR | Y | U | Y | U | U | N | Y | N | N | Y | Y | U | Y | N | N | NR | Poor | Fair
Lerma, 2017^70^ | Y | NR | Y | U | Y | Y | Y | N | Y | N | N | N | Y | Y | Y | N | N | Government | Fair | Fair
Mehrotra, 2019^63^ | Y | Y | U | Y | Y | Y | N | N | Y | N | Y | N | Y | Y | Y | Y | N | Government, University, NIDDK, DCI | Fair | Fair
Rahimipour, 2015^76^ | U | NR | U | U | Y | U | U | U | N | U | U | U | Y | U | Y | U | N | NR | Poor | Fair
Taraz, 2013^62^ | Y | U | Y | Y | Y | U | U | Y | Y | N | N | N | Y | Y | Y | N | N | University grant | Fair | Good
Thomas, 2017^78^ | Y | NR | N | U | Y | Y | U | N | Y | N | Y | N | Y | Y | Y | N | N | University grant | Fair | Fair
Tsay, 2004^72^ | NR | NR | Y | U | Y | U | U | N | Y | N | N | Y | Y | U | Y | N | N | Government | Poor | Fair
Wang, 2016^65^ | Y | Y | Y | Y | Y | U | Y | Y | Y | N | N | U | Y | Y | Y | N | N | NR | Fair | Poor
Widyaningrum, 2013^77^ | NR | NR | Y | U | Y | U | U | U | N | U | U | U | Y | U | Y | U | N | NR | Poor | Poor

Abbreviations: DCI = Dialysis Clinic Inc.; N = no; NA = not applicable; NIDDK = National Institute of Diabetes and Digestive and Kidney Diseases; NR = not reported; U = unclear; Y = yes

* Quality Rating Criteria:

1. Randomization adequate?
2. Allocation concealment adequate?
3. Groups similar at baseline?
4. Maintain comparable groups?
5. Eligibility criteria specified?
6. Outcome assessors masked?
7. Care provider masked?
8. Patient masked?
9. Reporting of attrition, crossovers, adherence, and contamination?
10. Important differential loss to follow-up or overall high loss to follow-up?
11. Intention-to-treat (ITT) analysis?
12. Post-randomization exclusions?
13. Were outcomes pre-specified and defined, and ascertained using accurate methods?
14. Intervention fidelity?
15. Follow-up long enough for outcomes to occur? (minimum 4 weeks for drugs)
16. Appropriate handling of missing data?
17. Evidence of selective outcome reporting?