# APPENDIX C QUALITY AND APPLICABILITY ASSESSMENT OF DIAGNOSTIC STUDIES

Study | Rating Criteria^*^
Study | Could the selection of patients have introduced bias? | | | | Could the conduct or interpretation of the index test have introduced bias? | | | | | Could the conduct or interpretation of the reference standard have introduced bias? | | | | | Could the patient flow have introduced bias? | | | | Applicability
Study | 1 | 2 | 3 | ROB | 4 | 5 | 6 | 7 | ROB | 8 | 9 | 10 | 11 | ROB | 12 | 13 | 14 | ROB | 15 | 16 | 17 | ROB
Alsuwaida, 2006^52^ | U | Y | U | Unclear | Y | U | U | Y | Unclear | Y | Y | U | Y | Unclear | Y | NA | U | Unclear | N | N | N | Low
Balogun, 2011^39^ | U | Y | Y | Unclear | Y | U | U | Y | Unclear | Y | U | U | U | Unclear | Y | Y | N | High | N | N | N | Low
Bautovich, 2018^48^ | U | Y | Y | Unclear | Y | U | NA | Y | Unclear | Y | Y | N | Y | High | Y | NA | Y | Low | N | N | N | Low
Chilcot, 2008^53^ | U | Y | Y | Unclear | U | U | NA | Y | Unclear | U | Y | U | U | Unclear | Y | NA | Y | Low | N | N | N | Low
Collister, 2019^49^ | Y | Y | Y | Low | U | U | U | Y | Unclear | U | U | U | U | Unclear | Y | NA | Y | Low | N | N | N | Low
Gencoz, 2007^42^ | Y | Y | U | Unclear | Y | Y | Y | Y | Low | Y | U | Y | U | Unclear | Y | Y | Y | Low | N | N | N | Low
Giordano, 2007^40^ | Y | U | Y | Unclear | U | Y | Y | Y | Unclear | Y | Y | U | Y | Unclear | Y | NA | N | High | N | N | N | Low
Grant, 2008^50^ | U | Y | Y | Unclear | U | U | NA | Y | Unclear | U | Y | U | Y | Unclear | Y | NA | Y | Low | N | N | N | Low
Hedayati, 2006^33^ | U | Y | Y | Unclear | Y | U | NA | Y | Unclear | U | Y | U | Y | Unclear | Y | NA | Y | Low | N | N | N | Low
Loosman, 2010^35^ | U | Y | Y | Unclear | Y | U | NA | Y | Unclear | Y | Y | Y | Y | Low | Y | NA | Y | Low | N | N | N | Low
Neitzer, 2012^46^ | U | Y | Y | Unclear | U | U | NA | Y | Unclear | U | U | NA | Y | Unclear | Y | NA | Y | Low | N | N | N | Low
Preljevic, 2012^36^ | U | Y | Y | Unclear | Y | U | NA | Y | Unclear | Y | U | Y | Y | Unclear | Y | NA | N | Low | N | N | N | Low
Troidle, 2003^47^ | Y | Y | Y | Low | N | U | U | Y | High | U | U | U | U | Unclear | Y | NA | Y | Low | N | N | N | Low
Van den Beukel, 2012^51^ | U | Y | Y | Unclear | U | U | U | Y | Unclear | U | U | U | Y | Unclear | Y | NA | Y | Low | N | N | N | Low
Wang, 2019^45^ | Y | Y | Y | Low | Y | U | U | Y | Unclear | Y | U | U | Y | Unclear | Y | NA | Y | Low | N | N | N | Low
Watnick, 2005^44^ | U | Y | Y | Unclear | Y | U | NA | Y | Unclear | Y | Y | U | Y | Unclear | Y | NA | Y | Low | N | N | N | Low

Abbreviations: N = no; NA = not applicable; ROB = risk of bias; U = unclear; Y = yes

* Questions (QUADAS-2^25^):

1. Consecutive or random sample of patients enrolled?
2. Was a case-control design avoided?
3. Did the study avoid inappropriate exclusions?
4. Was the index test interpreted without knowledge of the reference standard results?
5. Was staff trained in the use of the index test?
6. Was the fidelity of the index test monitored and/or reported?
7. Is the reference standard likely to correctly classify the target condition?
8. Was the reference standard interpreted without knowledge of the index test results?
9. Was staff trained in the assessment of the reference standard?
10. Was the fidelity of the reference test monitored and/or reported?
11. Was there an appropriate interval between the index test and reference standard?
12. Did all patients receive the same reference standard?
13. If a partial selection of patients received the reference standard, was it adjusted?
14. Were all patients included in the analysis?
15. Are there concerns that the study population differs from the review question?
16. Are there concerns that the index test, its conduct, or its interpretation differ from the review question?
17. Are there concerns that the reference standard, its conduct, or its interpretation differ from the review question?