# APPENDIX A SEARCH STRATEGIES

Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily 1946 to May 16, 2019

Date searched: May 17, 2019

# | Searches | Results
1 | Kidney Failure, Chronic/ | 90023
2 | (((chronic or endstage or end-stage or endstate or end-state or failure or long-term or maintenance) adj2 (kidney or renal)) or ESKD or ESKF or ESRD or ESRF).ti,ab,kf. | 173570
3 | Renal Dialysis/ or Hemofiltration/ or Hemodiafiltration/ or Hemodialysis, Home/ or Peritoneal Dialysis/ or Peritoneal Dialysis, Continuous Ambulatory/ | 112477
4 | (dialysis or haemodiafiltration or hemodiafiltration or haemo-diafiltration or hemo-diafiltration or haemofiltration or hemofiltration or haemo-filtration or hemo-filtration or haemodialysis or hemodialysis or haemo-dialysis or hemo-dialysis).ti,ab,kf. | 148887
5 | or/1-4 | 306563
6 | Depression/ or Depressive Disorder/ or Depressive Disorder, Major/ or Depressive Disorder, Treatment-Resistant/ | 196624
7 | (depressed or depressive or depression* or suicidal or suicide or suicides).ti,ab,kf. | 461502
8 | or/6-7 | 498556
9 | and/5,8 | 4467
10 | Brief Psychiatric Rating Scale/ or Diagnostic Self Evaluation/ or “Diagnostic Techniques and Procedures”/ or Mental Status Schedule/ or Neuropsychological Tests/ or Patient Health Questionnaire/ or Psychiatric Status Rating Scales/ or exp Psychological Tests/ or exp “Surveys and Questionnaires”/ | 1191872
11 | (checklist* or check-list* or questionnaire or questionnaires or instrument or instruments or inventory or inventories or scale or scales or schedule or schedules or screen or screened or screening or “Beck Depression” or BDI or BDI2 or “geriatric depression scale” or GDS or “Hamilton Rating Scale for Depression” or “Hospital Anxiety and Depression Scale” or HADS or “Kidney Disease Quality of Life” or KDQOL or “Medical Outcomes Study Short Form Health Survey 36” or MOS-SF36 or “Minnesota Multiphasic Personality Inventory” or MMPI or “Multiple Affect Adjective Check List” or MAACL or “Patient Health Questionnaire” or PHQ2 or PHQ-2 or PHQ9 or PHQ-9 or “PRIME-MD” or “Epidemiologic Studies Depression Scale” or CED or CESD or BREF or DASS21 or IDID or “Quick Inventory of Depressive Symptomatology Self-Report” or QIDS-SR or “RAND 36-Item Health Survey” or RAND-36 or “short form 36” or SF-36 or “Structured Clinical Interview” or SCID or “self-rating depression scale” or SDS or “Short Form Health Survey 36” or SF36).ti,ab,kf. | 2055783
12 | exp Behavior Therapy/ or exp Cognitive Behavioral Therapy/ or exp Mental Health Services/ or exp Psychotherapy/ or Psychosocial Support Systems/ or Social Support/ or Motivational Interviewing/ or Patient Participation/ | 348454
13 | (cognitive-behavior* or cognitive-behaviour* or intervention or interventions or nondrug or non-drug or nonpharmac* or non-pharmac* or pharmac* or program* or psych* or psychosocial or psycho-social or rehabilitation or therapy or therapies or treat*).ti,ab,kf. | 7986725
14 | Antidepressive Agents/ or Antidepressive Agents, Second-generation/ or Serotonin Uptake Inhibitors/ or “Serotonin and Noradrenaline Reuptake Inhibitors”/ or Adrenergic Uptake Inhibitors/ or 5-hydroxytryptophan/ or Amisulpride/ or Bupropion/ or Citalopram/ or Fluoxetine/ or Fluvoxamine/ or Maprotiline/ or Mianserin/ or Paroxetine/ or Quipazine/ or Ritanserin/ or Sulpiride/ or Trazodone/ or Tryptophan/ or Venlafaxine Hydrochloride/ or Viloxazine/ | 110464
15 | (antidepress* or anti-depress* or 5-hydroxytryptophan or Amisulpride or Bupropion or Citalopram or Escitalopram or Fluoxetine or Fluvoxamine or Maprotiline or Mianserin or Paroxetine or Quipazine or Ritanserin or Sulpiride or Trazodone or Tryptophan or Venlafaxine Hydrochloride or Viloxazine or SSRI or SSRIs or “selective serotonin reuptake” or “selective serotonin re-uptake” or SNRI or SNRIs or “Serotonin and Noradrenaline Reuptake Inhibitor” or “Serotonin and Noradrenaline Reuptake Inhibitors” or NRI or NRIs or “norepinephrine reuptake inhibitor” or “norepinephrine reuptake inhibitors”).ti,ab,kf. | 143600
16 | Antidepressive Agents, Tricyclic/ or Amitriptyline/ or Amoxapine/ or Clomipramine/ or Desipramine/ or Dothiepin/ or Doxepin/ or Imipramine/ or Iprindole/ or Lofepramine/ or Nortriptyline/ or Opipramol/ or Protriptyline/ or Trimipramine/ | 30787
17 | (Amitriptyline or Amoxapine or Clomipramine or Desipramine or Dothiepin or Doxepin or Imipramine or Iprindole or Lofepramine or Nortriptyline or Opipramol or Protriptyline or Trimipramine or Gabapentin or Sildenafil or Vardenafil).ti,ab,kf,nm. | 46116
18 | (nondrug or non-drug or nonpharmacolog* or non-pharmacolog*).ti,ab,kf. | 19983
19 | Exercise Therapy/ or Resistance Training/ | 43818
20 | (((aerobic or resistance) adj2 (exercis* or program* or therap* or train*)) or (exercise adj2 (program* or therap* or train*)) or cross-training).ti,ab,kf. | 59756
21 | Music Therapy/ | 3247
22 | music therapy.ti,ab,kf. | 2112
23 | or/10-22 | 9783531
24 | and/9,23 | 3317
25 | limit 24 to english language | 2949

PsycINFO 1806 to May Week 1 2019

Date searched: May 16, 2019

| Searches | Results
1 | Kidney Diseases/ | 2042
2 | (((chronic or endstage or end-stage or endstate or end-state or failure or long-term or maintenance) adj2 (kidney or renal)) or ESKD or ESKF or ESRD or ESRF).ti,ab. | 2810
3 | Dialysis/ or Hemodialysis/ | 1775
4 | (dialysis or haemodiafiltration or hemodiafiltration or haemo-diafiltration or hemo-diafiltration or haemofiltration or hemofiltration or haemo-filtration or hemo-filtration or haemodialysis or hemodialysis or haemo-dialysis or hemo-dialysis).ti,ab. | 2862
5 | or/1-4 | 5141
6 | “Depression (Emotion)”/ or Major Depression/ or Reactive Depression/ or Recurrent Depression/ or Treatment Resistant Depression/ | 140804
7 | (depressed or depressive or depression* or suicidal or suicide or suicides).ti,ab. | 317296
8 | or/6-7 | 323277
9 | and/5,8 | 865
10 | exp Measurement/ or exp Attitude Measures/ or exp “Checklist (Testing)”/ or exp Inventories/ or exp Psychological Assessment/ or exp Questionnaires/ or exp Rating Scales/ or exp Screening/ or exp Screening Tests/ or exp Standardized Tests/ or exp “Stress and Coping Measures”/ or exp Testing/ | 338213
11 | (checklist* or check-list* or questionnaire or questionnaires or instrument or instruments or inventory or inventories or scale or scales or schedule or schedules or screen or screened or screening or “Beck Depression” or BDI or BDI2 or “geriatric depression scale” or GDS or “Hamilton Rating Scale for Depression” or “Hospital Anxiety and Depression Scale” or HADS or “Kidney Disease Quality of Life” or KDQOL or “Medical Outcomes Study Short Form Health Survey 36” or MOS-SF36 or “Minnesota Multiphasic Personality Inventory” or MMPI or “Multiple Affect Adjective Check List” or MAACL or “Patient Health Questionnaire” or PHQ2 or PHQ-2 or PHQ9 or PHQ-9 or “PRIME-MD” or “Epidemiologic Studies Depression Scale” or CED or CESD or BREF or DASS21 or IDID or “Quick Inventory of Depressive Symptomatology Self-Report” or QIDS-SR or “RAND 36-Item Health Survey” or RAND-36 or “short form 36” or SF-36 or “Structured Clinical Interview” or SCID or “self-rating depression scale” or SDS or “Short Form Health Survey 36” or SF36).ti,ab. | 742562
12 | (“Beck Depression” or BDI or BDI2 or “geriatric depression scale” or GDS or “Hamilton Rating Scale for Depression” or “Hospital Anxiety and Depression Scale” or HADS or “Kidney Disease Quality of Life” or KDQOL or “Medical Outcomes Study Short Form Health Survey 36” or MOS-SF36 or “Minnesota Multiphasic Personality Inventory” or MMPI or “Multiple Affect Adjective Check List” or MAACL or “Patient Health Questionnaire” or PHQ2 or PHQ-2 or PHQ9 or PHQ-9 or PHQ-ADS or “PRIME-MD” or “Epidemiologic Studies Depression Scale” or CED or CESD or BREF or DASS21 or IDID or “Quick Inventory of Depressive Symptomatology Self-Report” or QIDS-SR or “RAND 36-Item Health Survey” or RAND-36 or “short form 36” or SF-36 or “Structured Clinical Interview” or SCID or “self-rating depression scale” or SDS or “Short Form Health Survey 36” or SF36).tm. | 121323
13 | exp Treatment/ | 713235
14 | exp Behavior Modification/ or exp Behavior Therapy/ or Biofeedback Training/ or Contingency Management/ or Self-management/ or Anxiety Management/ or Cognitive Therapy/ or Readiness to Change/ or Relaxation Therapy/ or Self-help Techniques/ or Self-monitoring/ or Stress Management/ | 68176
15 | (cognitive-behavior* or cognitive-behaviour* or intervention or interventions or nondrug or non-drug or nonpharmac* or non-pharmac* or pharmac* or program* or psych* or psychosocial or psycho-social or rehabilitation or therapy or therapies or treat*).ti,ab. | 2004054
16 | Antidepressant Drugs/ or Serotonin Norepinephrine Reuptake Inhibitors/ or Serotonin Reuptake Inhibitors/ or Tricyclic Antidepressant Drugs/ or Bupropion/ or Citalopram/ or Fluoxetine/ or Fluvoxamine/ or “Hydroxytryptophan (5-)”/ or MAPROTILINE/ or Mianserin/ or Paroxetine/ or RITANSERIN/ or Sulpiride/ or Trazodone/ or Tryptophan/ or Venlafaxine/ | 32404
17 | (antidepress* or anti-depress* or 5-hydroxytryptophan or Amisulpride or Bupropion or Citalopram or Escitalopram or Fluoxetine or Fluvoxamine or Maprotiline or Mianserin or Paroxetine or Quipazine or Ritanserin or Sulpiride or Trazodone or Tryptophan or Venlafaxine Hydrochloride or Viloxazine or SSRI or SSRIs or “selective serotonin reuptake” or “selective serotonin re-uptake” or SNRI or SNRIs or “Serotonin and Noradrenaline Reuptake Inhibitor” or “Serotonin and Noradrenaline Reuptake Inhibitors” or NRI or NRIs or “norepinephrine reuptake inhibitor” or “norepinephrine reuptake inhibitors”).ti,ab. | 55680
18 | (Amitriptyline or Amoxapine or Clomipramine or Desipramine or Dothiepin or Doxepin or Imipramine or Iprindole or Lofepramine or Nortriptyline or Opipramol or Protriptyline or Trimipramine or Gabapentin or Sildenafil or Vardenafil).ti,ab. | 12077
19 | (nondrug or non-drug or nonpharmacolog* or non-pharmacolog* or coping or psychosocial* or psycho-social* or “social support” or “social work*” or stress).ti,ab. | 373419
20 | exp Exercise/ | 24633
21 | (((aerobic or resistance) adj2 (exercis* or program* or therap* or train*)) or (exercise adj2 (program* or therap* or train*)) or cross-training).ti,ab. | 7962
22 | Music Therapy/ | 4568
23 | music therapy.ti,ab. | 3920
24 | or/10-23 | 2709627
25 | and/9,24 | 813
26 | limit 25 to english language | 708

Embase.com

Date search: May 17, 2019

# | Search | Result
#26 | #25 AND [embase]/lim NOT ([embase]/lim AND [medline]/lim) | 2,398 (https://www.embase.com/)
#25 | #9 AND #23 AND [english]/lim | 5,827 (https://www.embase.com/)
#24 | #9 AND #23 | 6,404 (https://www.embase.com/)
#23 | #10 OR #11 OR #12 OR #13 OR #14 OR #15 OR #16 OR #17 OR #18 OR #19 OR #20 OR #21 OR #22 | 11,480,368 (https://www.embase.com/)
#22 | ‘music therapy’:ti,ab,kw | 3,312 (https://www.embase.com/)
#21 | ‘music therapy’/de | 6,432 (https://www.embase.com/)
#20 | (((aerobic OR resistance) NEAR/2 (exercis* OR program* OR therap* OR train*)):ti,ab,kw) OR ((exercise NEAR/2 (program* OR therap* OR train*)):ti,ab,kw) OR ‘cross training’:ti,ab,kw | 85,478 (https://www.embase.com/)
#19 | ‘kinesiotherapy’/de OR ‘resistance training’/de | 46,613 (https://www.embase.com/)
#18 | nondrug:ti,ab,kw OR ‘non drug’:ti,ab,kw OR nonpharmacolog*:ti,ab,kw OR ‘non pharmacolog*’:ti,ab,kw | 28,848 (https://www.embase.com/)
#17 | amitriptyline:ti,ab,kw OR amoxapine:ti,ab,kw OR clomipramine:ti,ab,kw OR desipramine:ti,ab,kw OR dothiepin:ti,ab,kw OR doxepin:ti,ab,kw OR imipramine:ti,ab,kw OR iprindole:ti,ab,kw OR lofepramine:ti,ab,kw OR nortriptyline:ti,ab,kw OR opipramol:ti,ab,kw OR protriptyline:ti,ab,kw OR trimipramine:ti,ab,kw OR gabapentin:ti,ab,kw OR sildenafil:ti,ab,kw OR vardenafil:ti,ab,kw | 49,716 (https://www.embase.com/)
#16 | ‘tricyclic antidepressant agent’/de OR ‘amitriptyline’/de OR ‘clomipramine’/de OR ‘desipramine’/de OR ‘dosulepin’/de OR ‘doxepin’/de OR ‘imipramine’/de OR ‘iprindole’/de OR ‘lofepramine’/de OR ‘nortriptyline’/de OR ‘opipramol’/de OR ‘protriptyline’/de OR ‘trimipramine’/de | 108,601 (https://www.embase.com/)
#15 | ((antidepress*:ti,ab,kw OR ‘anti depress*’:ti,ab,kw OR ‘5 hydroxytryptophan’:ti,ab,kw OR amisulpride:ti,ab,kw OR bupropion:ti,ab,kw OR citalopram:ti,ab,kw OR escitalopram:ti,ab,kw OR fluoxetine:ti,ab,kw OR fluvoxamine:ti,ab,kw OR maprotiline:ti,ab,kw OR mianserin:ti,ab,kw OR paroxetine:ti,ab,kw OR quipazine:ti,ab,kw OR ritanserin:ti,ab,kw OR sulpiride:ti,ab,kw OR trazodone:ti,ab,kw OR tryptophan:ti,ab,kw OR ‘venlafaxine hydrochloride’:ti,ab,kw OR viloxazine:ti,ab,kw OR ssri:ti,ab,kw OR ssris:ti,ab,kw OR ‘selective serotonin reuptake’:ti,ab,kw OR ‘selective serotonin re-uptake’:ti,ab,kw OR snri:ti,ab,kw OR snris:ti,ab,kw OR serotonin:ti,ab,kw) AND ‘noradrenaline reuptake inhibitor’:ti,ab,kw OR serotonin:ti,ab,kw) AND ‘noradrenaline reuptake inhibitors’:ti,ab,kw OR nri:ti,ab,kw OR nris:ti,ab,kw OR ‘norepinephrine reuptake inhibitor’:ti,ab,kw OR ‘norepinephrine reuptake inhibitors’:ti,ab,kw | 5,610 (https://www.embase.com/)
#14 | ‘antidepressant agent’/de OR ‘serotonin uptake inhibitor’/de OR ‘serotonin noradrenalin reuptake inhibitor’/de OR ‘adrenergic receptor affecting agent’/de OR ‘5 hydroxytryptophan’/de OR ‘amisulpride’/de OR ‘amfebutamone’/de OR ‘citalopram’/de OR ‘fluoxetine’/de OR ‘fluvoxamine’/de OR ‘maprotiline’/de OR ‘mianserin’/de OR ‘paroxetine’/de OR ‘quipazine’/de OR ‘ritanserin’/de OR ‘sulpiride’/de OR ‘trazodone’/de OR ‘tryptophan’/de OR ‘venlafaxine’/de OR ‘viloxazine’/de | 252,721 (https://www.embase.com/)
#13 | ‘cognitive behavior*’:ti,ab,kw OR ‘cognitive behaviour*’:ti,ab,kw OR intervention:ti,ab,kw OR interventions:ti,ab,kw OR nondrug:ti,ab,kw OR ‘non drug’:ti,ab,kw OR nonpharmac*:ti,ab,kw OR ‘non pharmac*’:ti,ab,kw OR pharmac*:ti,ab,kw OR program*:ti,ab,kw OR psych*:ti,ab,kw OR psychosocial:ti,ab,kw OR ‘psycho social’:ti,ab,kw OR rehabilitation:ti,ab,kw OR therapy:ti,ab,kw OR therapies:ti,ab,kw OR treat*:ti,ab,kw | 10,743,323 (https://www.embase.com/)
#12 | ‘behavior therapy’/de OR ‘cognitive behavioral therapy’/de OR ‘mental health service’/de OR ‘psychotherapy’/de OR ‘psychosocial care’/de OR ‘social support’/de OR ‘motivational interviewing’/de OR ‘patient participation’/de | 309,109 (https://www.embase.com/)
#11 | (checklist*:ti,ab,kw OR ‘check list*’:ti,ab,kw OR questionnaire:ti,ab,kw OR questionnaires:ti,ab,kw OR instrument:ti,ab,kw OR instruments:ti,ab,kw OR inventory:ti,ab,kw OR inventories:ti,ab,kw OR scale:ti,ab,kw OR scales:ti,ab,kw OR schedule:ti,ab,kw OR schedules:ti,ab,kw OR screen:ti,ab,kw OR screened:ti,ab,kw OR screening:ti,ab,kw OR ‘beck depression’:ti,ab,kw OR bdi:ti,ab,kw OR bdi2:ti,ab,kw OR ‘geriatric depression scale’:ti,ab,kw OR gds:ti,ab,kw OR ‘hamilton rating scale for depression’:ti,ab,kw OR ‘hospital anxiety’:ti,ab,kw) AND ‘depression scale’:ti,ab,kw OR hads:ti,ab,kw OR ‘kidney disease quality of life’:ti,ab,kw OR kdqol:ti,ab,kw OR ‘medical outcomes study short form health survey 36’:ti,ab,kw OR ‘mos sf36’:ti,ab,kw OR ‘minnesota multiphasic personality inventory’:ti,ab,kw OR mmpi:ti,ab,kw OR ‘multiple affect adjective check list’:ti,ab,kw OR maacl:ti,ab,kw OR ‘patient health questionnaire’:ti,ab,kw OR phq2:ti,ab,kw OR ‘phq 2’:ti,ab,kw OR phq9:ti,ab,kw OR ‘phq 9’:ti,ab,kw OR ‘prime-md’:ti,ab,kw OR ‘epidemiologic studies depression scale’:ti,ab,kw OR ced:ti,ab,kw OR cesd:ti,ab,kw OR bref:ti,ab,kw OR dass21:ti,ab,kw OR idid:ti,ab,kw OR ‘quick inventory of depressive symptomatology self-report’:ti,ab,kw OR ‘qids sr’:ti,ab,kw OR ‘rand 36-item health survey’:ti,ab,kw OR ‘rand 36’:ti,ab,kw OR ‘short form 36’:ti,ab,kw OR ‘sf 36’:ti,ab,kw OR ‘structured clinical interview’:ti,ab,kw OR scid:ti,ab,kw OR ‘selfrating depression scale’:ti,ab,kw OR sds:ti,ab,kw OR ‘short form health survey 36’:ti,ab,kw OR sf36:ti,ab,kw | 219,556 (https://www.embase.com/)
#10 | ‘brief psychiatric rating scale’/de OR ‘diagnostic procedure’/de OR ‘neuropsychological test’/de OR ‘patient health questionnaire’/de OR ‘psychological rating scale’/de OR ‘psychologic test’/de OR ‘questionnaire’/de | 825,223 (https://www.embase.com/)
#9 | #5 AND #8 | 8,835 (https://www.embase.com/)
#8 | #6 OR #7 | 773,952 (https://www.embase.com/)
#7 | depressed:ti,ab,kw OR depressive:ti,ab,kw OR depression*:ti,ab,kw OR suicidal:ti,ab,kw OR suicide:ti,ab,kw OR suicides:ti,ab,kw | 620,970 (https://www.embase.com/)
#6 | ‘depression’/exp | 459,806 (https://www.embase.com/)
#5 | #1 OR #2 OR #3 OR #4 | 445,287 (https://www.embase.com/)
#4 | dialysis:ti,ab,kw OR haemodiafiltration:ti,ab,kw OR hemodiafiltration:ti,ab,kw OR ‘haemo diafiltration’:ti,ab,kw OR ‘hemo diafiltration’:ti,ab,kw OR haemofiltration:ti,ab,kw OR hemofiltration:ti,ab,kw OR ‘haemo filtration’:ti,ab,kw OR ‘hemo filtration’:ti,ab,kw OR haemodialysis:ti,ab,kw OR hemodialysis:ti,ab,kw OR ‘haemo dialysis’:ti,ab,kw OR ‘hemo dialysis’:ti,ab,kw | 206,562 (https://www.embase.com/)
#3 | ‘hemodialysis’/exp OR ‘hemofiltration’/exp OR ‘hemodiafiltration’/exp OR ‘peritoneal dialysis’/exp | 140,123 (https://www.embase.com/)
#2 | (((chronic OR endstage OR ‘end stage’ OR endstate OR ‘end state’ OR failure OR ‘long term’ OR maintenance) NEAR/2 (kidney OR renal)):ti,ab,kw) OR eskd:ti,ab,kw OR eskf:ti,ab,kw OR esrd:ti,ab,kw OR esrf:ti,ab,kw | 259,194 (https://www.embase.com/)
#1 | ‘chronic kidney failure’/exp | 136,333 (https://www.embase.com/)

EBM Reviews:

Cochrane Central Register of Controlled Trials April 2019

Cochrane Database of Systematic Reviews 2005 to May 2, 2019

Database of Abstracts of Reviews of Effects 1st Quarter 2016

Health Technology Assessment 4th Quarter 2016

Date searched: May 16, 2019

# | Searches | Results
1 | (((chronic or endstage or end-stage or endstate or end-state or failure or long-term or maintenance) adj2 (kidney or renal)) or ESKD or ESKF or ESRD or ESRF).ti,ab. | 18139
2 | (dialysis or haemodiafiltration or hemodiafiltration or haemo-diafiltration or hemo-diafiltration or haemofiltration or hemofiltration or haemo-filtration or hemo-filtration or haemodialysis or hemodialysis or haemo-dialysis or hemo-dialysis).ti,ab. | 16708
3 | or/1-2 | 28646
4 | (depressed or depressive or depression* or suicidal or suicide or suicides).ti,ab. | 70284
5 | and/3-4 | 564
6 | (checklist* or check-list* or questionnaire or questionnaires or instrument or instruments or inventory or inventories or scale or scales or schedule or schedules or screen or screened or screening or “Beck Depression” or BDI or BDI2 or “geriatric depression scale” or GDS or “Hamilton Rating Scale for Depression” or “Hospital Anxiety and Depression Scale” or HADS or “Kidney Disease Quality of Life” or KDQOL or “Medical Outcomes Study Short Form Health Survey 36” or MOS-SF36 or “Minnesota Multiphasic Personality Inventory” or MMPI or “Multiple Affect Adjective Check List” or MAACL or “Patient Health Questionnaire” or PHQ2 or PHQ-2 or PHQ9 or PHQ-9 or “PRIME-MD” or “Epidemiologic Studies Depression Scale” or CED or CESD or BREF or DASS21 or IDID or “Quick Inventory of Depressive Symptomatology Self-Report” or QIDS-SR or “RAND 36-Item Health Survey” or RAND-36 or “short form 36” or SF-36 or “Structured Clinical Interview” or SCID or “self-rating depression scale” or SDS or “Short Form Health Survey 36” or SF36).ti,ab. | 286914
7 | (cognitive-behavior* or cognitive-behaviour* or intervention or interventions or nondrug or non-drug or nonpharmac* or non-pharmac* or pharmac* or program* or psych* or psychosocial or psycho-social or rehabilitation or therapy or therapies or treat*).ti,ab. | 1033100
8 | (antidepress* or anti-depress* or 5-hydroxytryptophan or Amisulpride or Bupropion or Citalopram or Escitalopram or Fluoxetine or Fluvoxamine or Maprotiline or Mianserin or Paroxetine or Quipazine or Ritanserin or Sulpiride or Trazodone or Tryptophan or Venlafaxine Hydrochloride or Viloxazine or SSRI or SSRIs or “selective serotonin reuptake” or “selective serotonin re-uptake” or SNRI or SNRIs or “Serotonin and Noradrenaline Reuptake Inhibitor” or “Serotonin and Noradrenaline Reuptake Inhibitors” or NRI or NRIs or “norepinephrine reuptake inhibitor” or “norepinephrine reuptake inhibitors”).ti,ab. | 23770
9 | (Amitriptyline or Amoxapine or Clomipramine or Desipramine or Dothiepin or Doxepin or Imipramine or Iprindole or Lofepramine or Nortriptyline or Opipramol or Protriptyline or Trimipramine or Gabapentin or Sildenafil or Vardenafil).ti,ab. | 10032
10 | (nondrug or non-drug or nonpharmacolog* or non-pharmacolog*).ti,ab. | 4995
11 | (((aerobic or resistance) adj2 (exercis* or program* or therap* or train*)) or (exercise adj2 (program* or therap* or train*)) or cross-training).ti,ab. | 29280
12 | music therapy.ti,ab. | 1091
13 | or/6-12 | 1100240
14 | and/5,13 | 533

ClinicalTrials.gov

Date searched: May 16, 2019

(depressed OR depressive OR depression* OR suicidal OR suicide OR suicides) AND INFLECT EXACT (“Active, not recruiting” OR “Completed” OR “Suspended” OR “Terminated” OR “Withdrawn” OR “Unknown status”) [OVERALL-STATUS] AND ((chronic OR endstage OR end-stage OR failure) AND (kidney OR renal) OR ESKD OR ESKF OR ESRD OR ESRF OR dialysis OR haemodiafiltration OR hemodiafiltration OR haemo-diafiltration OR hemo-diafiltration OR haemofiltration OR hemofiltration OR haemo-fi) [DISEASE] = 83 results

WHO ICTRP

Date searched: May 16, 2019

(((chronic OR endstage OR end-stage OR failure) AND (kidney OR renal)) OR ESKD OR ESKF OR ESRD OR ESRF) AND (depress* OR suicid*) = 7 trials

VA HSR&D

https://www.hsrd.research.va.gov/research/

Date searched: May 16, 2019

Separately searched terms: kidney and renal. Reviewed result lists = 0 studies found.