# References

1 World Health Organization. Improving Access to Epilepsy Care. Available at: https://www.who.int/mental_health/neurology/epilepsy/en/. Accessed December 20, 2018.
2 Rehman R, Kelly PR, Husain AM, . Characteristics of Veterans diagnosed with seizures within Veterans Health Administration. J Rehabil Res Dev. 2015;52(7):751–62.26745205
3 Kanner AM. Management of psychiatric and neurological comorbidities in epilepsy. Nat Rev Neurol. 2016;12(2):106–16.26782334
4 Nevalainen O, Ansakorpi H, Simola M, . Epilepsy-related clinical characteristics and mortality: a systematic review and meta-analysis. Neurology. 2014;83(21):1968–77.25339211
5 Thurman DJ, Logroscino G, Beghi E, . The burden of premature mortality of epilepsy in high-income countries: A systematic review from the Mortality Task Force of the International League Against Epilepsy. Epilepsia. 2017;58(1):17–26.27888514
6 Liporace J, D’Abreu A. Epilepsy and women’s health: family planning, bone health, menopause, and menstrual-related seizures. Mayo Clin Proc. 2003;78(4):497–506.12683703
7 Smaldone M, Sukkarieh T, Reda A, . Epilepsy and erectile dysfunction: a review. Seizure. 2004;13(7):453–9.15324820
8 Morrell MJ. Stigma and epilepsy. Epilepsy Behav. 2002;3(6S2):21–25.12609302
9 Tian N, Boring M, Kobau R, . Active epilepsy and seizure control in adults - United States, 2013 and 2015. MMWR Morb Mortal Wkly Rep. 2018;67(15):437–442.29672474
10 Buck D, Baker GA, Chadwick DW, . Factors influencing compliance with antiepileptic drug regimes. Seizure. 1997;6(2):87–93.9153719
11 Farooq S, Naeem F. Tackling nonadherence in psychiatric disorders: current opinion. Neuropsychiatr Dis Treat. 2014;10:1069–77.24966677
12 U.S. Centers For Disease Controls and Prevention Epilepsy Program. About one-half of adults with active epilepsy and seizures have annual family incomes under $25,000: The 2010 and 2013 US National Health Interview Surveys. Epilepsy Behav. 2016;58:33–4.27039018
13 Samsonsen C, Reimers A, Brathen G, . Nonadherence to treatment causing acute hospitalizations in people with epilepsy: an observational, prospective study. Epilepsia. 2014;55(11):e125–8.25252007
14 Devinsky O, Ryvlin P, Friedman D. Preventing sudden unexpected death in epilepsy. JAMA Neurol. 2018;75(5):531–532.29710173
15 Institute of Medicine. Epilepsy Across the Spectrum: Promoting Health and Understanding. 2012. Available at: https://www.nap.edu/catalog/13379/epilepsy-across-the-spectrum-promoting-health-and-understanding. Accessed October 22, 2018.
16 Coleman K, Austin BT, Brach C, . Evidence on the Chronic Care Model in the new millennium. Health Aff (Millwood). 2009;28(1):75–85.19124857
17 Davy C, Bleasel J, Liu H, . Effectiveness of chronic care models: opportunities for improving healthcare practice and health outcomes: a systematic review. BMC Health Serv Res. 2015;15:194.25958128
18 Franek J. Self-management support interventions for persons with chronic disease: an evidence-based analysis. Ont Health Technol Assess Ser. 2013;13(9):1–60.
19 Jackson GL, Powers BJ, Chatterjee R, . Improving patient care. The patient centered medical home: a systematic review. Ann Intern Med. 2013;158(3):169–78.24779044
20 Center for Medicare & Medicaid Innovation. Comprehensive Primary Care Plus. Innovation Models. Available at: https://innovation.cms.gov/initiatives/Comprehensive-Primary-Care-Plus. Accessed May 17, 2018.
21 Barlow J, Wright C, Sheasby J, . Self-management approaches for people with chronic conditions: a review. Patient Educ Couns. 2002;48(2):177–87.12401421
22 Warsi A, Wang PS, LaValley MP, . Self-management education programs in chronic disease: a systematic review and methodological critique of the literature. Arch Intern Med. 2004;164(15):1641–9.15302634
23 Schaffler J, Leung K, Tremblay S, . The effectiveness of self-management interventions for individuals with low health literacy and/or low income: a descriptive systematic review. J Gen Intern Med. 2018;33(4):510–523.29427178
24 Bradley PM, Lindsay B, Fleeman N. Care delivery and self management strategies for adults with epilepsy. Cochrane Database Syst Rev. 2016;2:CD006244.26842929
25 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. PLoS Med. 2009;6(7):e1000097.19621072
26 Glasgow RE, Davis CL, Funnell MM, . Implementing practical interventions to support chronic illness self-management. Jt Comm J Qual Saf. 2003;29(11):563–74.14619349
27 Jonkman NH, Schuurmans MJ, Jaarsma T, . Self-management interventions: proposal and validation of a new operational definition. J Clin Epidemiol. 2016;80:34–42.27531245
28 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors Accessed May 17, 2018.
29 Evidence Partners Inc. DistillerAI website. Available at: https://www.evidencepartners.com/distiller-ai/. Accessed October 12, 2018.
30 Critical Appraisal Skills Programme (CASP). CASP Qualitative Checklist. Available at: http://www.casp-uk.net/casp-tools-checklists. Accessed May 17, 2018.
31 Hong QN, Pluye P, Fàbregues S, . Mixed Methods Appraisal Tool (MMAT), version 2018. Registration of Copyright (#1148552), Canadian Intellectual Property Office, Industry Canada. Available at: http://mixedmethodsappraisaltoolpublic.pbworks.com/w/page/127425845/Download%20the%20MMAT. Accessed October 11, 2018.
32 Cohen J. Statistical Power Analysis for the Behavioral Sciences. 2nd ed. Hillsdale, NJ: Erlbaum; 1988.
33 Knapp G, Hartung J. Improved tests for a random effects meta-regression with a single covariate. Stat Med. 2003;22(17):2693–710.12939780
34 Gale NK, Heath G, Cameron E, . Using the framework method for the analysis of qualitative data in multi-disciplinary health research. BMC Med Res Methodol. 2013;13:117.24047204
35 Thomas J, Harden A. Methods for the thematic synthesis of qualitative research in systematic reviews. BMC Med Res Methodol. 2008;8:45.18616818
36 Sallis JF, Owen N, Fisher E. Ecological Models of Health Behavior. In: Health behavior: Theory, Research, and Practice. 5th Edition. 2015:43–64.
37 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
38 Al-Aqeel S, Al-Sabhan J. Strategies for improving adherence to antiepileptic drug treatment in patients with epilepsy. Cochrane Database Syst Rev. 2011(1):Cd008312.21249705
39 Beatty L, Lambert S. A systematic review of internet-based self-help therapeutic interventions to improve distress and disease-control among adults with chronic health conditions. Clin Psychol Rev. 2013;33(4):609–22.23603521
40 Bradley PM, Lindsay B. Care delivery and self-management strategies for adults with epilepsy. Cochrane Database Syst Rev. 2008(1):Cd006244.18254097
41 Edward KL, Cook M, Giandinoto JA. An integrative review of the benefits of self-management interventions for adults with epilepsy. Epilepsy Behav. 2015;45:195–204.25843342
42 Gandy M, Sharpe L, Perry KN. Cognitive behavior therapy for depression in people with epilepsy: a systematic review. Epilepsia. 2013;54(10):1725–34.24032437
43 Smith A, McKinlay A, Wojewodka G, . A systematic review and narrative synthesis of group self-management interventions for adults with epilepsy. BMC Neurol. 2017;17(1):114.28623909
44 Taylor SJC, Pinnock H, Epiphaniou E, . A rapid synthesis of the evidence on interventions supporting self-management for people with long-term conditions: PRISMS - Practical systematic Review of Self-Management Support for long-term conditions. Health Serv Deliv Res. 2014;2:53.
45 O’Rourke G, O’Brien JJ. Identifying the barriers to antiepileptic drug adherence among adults with epilepsy. Seizure. 2017;45:160–168.28063375
46 Caller TA, Ferguson RJ, Roth RM, . A cognitive behavioral intervention (HOBSCOTCH) improves quality of life and attention in epilepsy. Epilepsy Behav. 2016;57(Pt A):111–117.26943948
47 DiIorio C, Bamps Y, Walker ER, . Results of a research study evaluating WebEase, an online epilepsy self-management program. Epilepsy Behav. 2011;22(3):469–74.21889413
48 Fraser RT, Johnson EK, Lashley S, . PACES in epilepsy: Results of a self-management randomized controlled trial. Epilepsia. 2015;56(8):1264–74.26122460
49 Gandy M, Sharpe L, Nicholson Perry K, . Cognitive behaviour therapy to improve mood in people with epilepsy: a randomised controlled trial. Cogn Behav Ther. 2014;43(2):153–66.24635701
50 Haut SR, Lipton RB, Cornes S, . Behavioral interventions as a treatment for epilepsy: A multicenter randomized controlled trial. Neurology. 2018;90(11):e963–e970.29444968
51 Helgeson DC, Mittan R, Tan SY, . Sepulveda Epilepsy Education: the efficacy of a psychoeducational treatment program in treating medical and psychosocial aspects of epilepsy. Epilepsia. 1990;31(1):75–82.2303015
52 Leenen LAM, Wijnen BFM, Kessels AGH, . Effectiveness of a multicomponent self-management intervention for adults with epilepsy (ZMILE study): A randomized controlled trial. Epilepsy Behav. 2018;80:259–265.29449140
53 May TW, Pfafflin M. The efficacy of an educational treatment program for patients with epilepsy (MOSES): results of a controlled, randomized study. Modular Service Package Epilepsy. Epilepsia. 2002;43(5):539–49.12027917
54 McLaughlin DP, McFarland K. A randomized trial of a group based cognitive behavior therapy program for older adults with epilepsy: the impact on seizure frequency, depression and psychosocial well-being. J Behav Med. 2011;34(3):201–7.20927577
55 Puskarich CA, Whitman S, Dell J, . Controlled examination of effects of progressive relaxation training on seizure reduction. Epilepsia. 1992;33(4):675–80.1628583
56 Tan SY, Bruni J. Cognitive-behavior therapy with adult patients with epilepsy: a controlled outcome study. Epilepsia. 1986;27(3):225–33.3516668
57 Ridsdale L, McKinlay A, Wojewodka G, . Self-management education for adults with poorly controlled epILEpsy [SMILE (UK)]: a randomised controlled trial. Health Technol Assess. 2018;22(21):1–142.
58 Sajatovic M, Colon-Zimmermann K, Kahriman M, . A 6-month prospective randomized controlled trial of remotely delivered group format epilepsy self-management versus waitlist control for high-risk people with epilepsy. Epilepsia. 2018;59(9):1684–1695.30098003
59 Gillham RA. Refractory epilepsy: an evaluation of psychological methods in outpatient management. Epilepsia. 1990;31(4):427–32.2196170
60 Gunter MJ, Brixner D, von Worley A, . Impact of a seizure disorder disease management program on patient-reported quality of life. Dis Manag. 2004;7(4):333–47.15671790
61 Wiebe S, Matijevic S, Eliasziw M, . Clinically important change in quality of life in epilepsy. J Neurol Neurosurg Psychiatry. 2002;73(2):116–120.12122166
62 Atkinson-Clark E, Charokopou M, Van Osselaer N, . A discrete-choice experiment to elicit preferences of patients with epilepsy for self-management programs. Epilepsy Behav. 2018;79:58–67.29248866
63 Begley C, Shegog R, Harding A, . Longitudinal feasibility of MINDSET: a clinic decision aid for epilepsy self-management. Epilepsy Behav. 2015;44:143–50.25705825
64 Johnson EK, Fraser RT, Miller JW, . A comparison of epilepsy self-management needs: provider and patient perspectives. Epilepsy Behav. 2012;25(2):150–5.23032121
65 Laybourne AH, Morgan M, Watkins SH, . Self-management for people with poorly controlled epilepsy: Participants’ views of the UK Self-Management in epILEpsy (SMILE) program. Epilepsy Behav. 2015;52(Pt A):159–64.26426353
66 Leenen LAM, Wijnen BFM, van Haastregt JCM, . Process evaluation of a multi-component self-management intervention for adults with epilepsy (ZMILE study). Epilepsy Behav. 2017;73:64–70.28623752
67 Ridsdale L, Philpott SJ, Krooupa AM, . People with epilepsy obtain added value from education in groups: results of a qualitative study. Eur J Neurol. 2017;24(4):609–616.28181344
68 Snape DA, Morgan M, Ridsdale L, . Developing and assessing the acceptability of an epilepsy first aid training intervention for patients who visit UK emergency departments: A multi-method study of patients and professionals. Epilepsy Behav. 2017;68:177–185.28213317
69 Walker ER, Bamps Y, Burdett A, . Social support for self-management behaviors among people with epilepsy: a content analysis of the WebEase program. Epilepsy Behav. 2012;23(3):285–90.22364762
70 Leenen LAM, Wijnen BFM, de Kinderen RJA, . Are people with epilepsy using eHealth-tools? Epilepsy Behav. 2016;64(Part A):268–272.27780086
71 Clark NM, Stoll S, Youatt EJ, . Fostering epilepsy self management: The perspectives of professionals. Epilepsy Behav. 2010;19(3):255–263.21145491
72 Fraser RT, Johnson EK, Miller JW, . Managing epilepsy well: Self-management needs assessment. Epilepsy Behav. 2011;20(2):291–298.21273135
73 Buelow JM. Epilepsy management issues and techniques. J Neurosci Nurs. 2001;33(5):260–269.11668884
74 Begley C, Chong J, Shegog R, . MINDSET: Clinical feasibility of utilizing the revised epilepsy self-management tool for Spanish speaking patients. Epilepsy Behav. 2018;88:218–226.30300871
75 Toivonen KI, Zernicke K, Carlson LE. Web-Based Mindfulness Interventions for People With Physical Health Conditions: Systematic Review. J Med Internet Res. 2017;19(8):e303.28860106
76 Lorig KR, Holman H. Self-management education: history, definition, outcomes, and mechanisms. Ann Behav Med. 2003;26(1):1–7.12867348
77 U.S. Department of Veterans Affairs. Whole Health For Life. Available at: https://www.va.gov/patientcenteredcare/. Accessed December 13, 2018.
78 U.S. Department of Veterans Affairs. Patient Care Services. Available at: https://www.patientcare.va.gov/primarycare/pact/Resources.asp. Accessed October 22, 2018.
79 Centers for Medicare and Medicaid Services. Diabetes self-management training. Available at: https://www.medicare.gov/coverage/diabetes-self-management-training. Accessed October 22, 2018.
80 Centers for Medicare and Medicaid Services. Chronic care management services. Available at: https://www.medicare.gov/coverage/chronic-care-management-services. Accessed October 22, 2018.
81 U.S. Department of Veterans Affairs. QUIET (Quality Indicators in Epilepsy Treatment) tool. Available at: https://www.epilepsy.va.gov/QUIET/index.asp. Accessed October 22, 2018.
82 Harkin B, Webb TL, Chang BP, . Does monitoring goal progress promote goal attainment? A meta-analysis of the experimental evidence. Psychol Bull. 2016;142(2):198–229.26479070
83 Escoffery C, McGee R, Bidwell J, . A review of mobile apps for epilepsy self-management. Epilepsy Behav. 2018;81:62–69.29494935
84 U.S. Department of Veterans Affairs. QUERI (Quality Enhancement Research Initiative. Available at: https://www.queri.research.va.gov/about/default.cfm. Accessed October 22, 2018.
85 Thompson NJ, Walker ER, Obolensky N, . Distance delivery of mindfulness-based cognitive therapy for depression: project UPLIFT. Epilepsy Behav. 2010;19(3):247–54.20851055
86 Adam GP, Springs S, Trikalinos T, . Does information from ClinicalTrials.gov increase transparency and reduce bias? Results from a five-report case series. Syst Rev. 2018;7(1):59.29661214