# Summary and Discussion

We evaluated self-management interventions for patients with epilepsy, examining effects on a range of outcomes of importance to patients, clinicians, and policymakers. Our review is unique in its use of a standard definition for self-management, focus on high-quality study designs, and rigorous analysis of studies that address facilitators and barriers to implementation and adoption of self-management interventions. We identified 15 studies addressing the effects of self-management and 13 studies that addressed implementation and adoption. Only 1 specifically included Veterans. We identified 2 broad categories for self-management interventions: (1) educationally focused interventions created for patients with epilepsy, where skill acquisition was often implicitly targeted in the process, and (2) established psychosocial therapies such as CBT that were adapted for people with epilepsy, where the educational component was often implicit. We found limited evidence for benefit on a priori selected primary or secondary outcomes. Educational self-management interventions may improve the use of self-management practices, and quality of life may improve with therapy-based self-management approaches. There was low to moderate certainty of no improvement in seizure rates across self-management interventions. Sparse evidence suggested possible benefit of psychosocial therapy interventions on self-efficacy. Effects on employment and health care utilization were not reported.

Studies of barriers and facilitators to implementation and adoption of epilepsy self-management interventions addressed factors primarily at the patient level or program level. No studies directly addressed implementation and adoption issues for large health systems such as the VHA. Important themes that could inform the development, implementation, and/or adoption of future self-management interventions included (1) the desire of patients with epilepsy to be involved in the development of intervention content, (2) recognition that cognitive limitations may affect engagement and adherence, and (3) the need for clinicians who are appropriately trained to provide self-management interventions and whose job function specifically includes this role.

Previous literature reviews have focused narrowly on group-based interventions,^43^ single therapeutic techniques,^42^ or interventions such as those to improve antiepileptic drug adherence^38^ that would not meet standard definitions for self-management. Others have addressed self-management interventions for individuals with chronic health conditions more generally,^39,44,75^ and diverse approaches including care delivery redesigns.^24,41^ None addressed implementation issues. A rapid synthesis of 30 prior systematic reviews for long-term conditions (LTCs) concluded “Supporting self-management is inseparable from the high-quality care for LTCs.”^44^ Consistent with our findings, authors of prior reviews that focused on epilepsy found limited evidence to support an effect on the outcomes of interest other than epilepsy self-management. Some reviews reported benefit for outcomes (eg, emotional well-being) that we did not consider.^43^ Previous review authors noted that findings were limited by unclear risk of bias, non-reporting of intervention fidelity, and heterogeneity of outcome measures observed across studies. Across these previous reviews, no single intervention was found to be consistently effective across all outcomes of interest. In contrast to our study, these reviews elected not to perform meta-analyses because of the diversity of study designs (randomized and nonrandomized), interventions, and in some cases, patient populations. We established study eligibility criteria that narrowed the scope of eligible studies and conducted limited meta-analyses of randomized trials by intervention category. We think these summary estimates facilitate understanding of intervention effects.

## Clinical and Policy Implications

Self-management of chronic illness that is aligned with an individual’s values and preferences is considered an important component in delivering patient-centered care in the VHA,^76,77^ and is a pillar of VHA’s Patient Aligned Care Teams (PACT).^78^ Outside of the VHA, Medicare covers self-management services for patients with diabetes mellitus only,^79^ but for other chronic conditions, services are covered only within the context of chronic disease management programs for multiple chronic diseases.^80^

For patients with epilepsy, the Institute of Medicine (IOM) in 2012 recommended “access to relevant and usable knowledge … to achieve optimal self-management of their epilepsy”^15^ and that these resources allow for tailoring to individual needs. Further, the IOM recommended that research be devoted to “evaluating, replicating, and expanding the use of epilepsy self-management programs.”^15^ This recommendation was based on a careful review of evidence by a multidisciplinary panel but did not include a formal systematic review. Our protocol-driven review addresses the IOM mandate to evaluate existing research and may be of broader interest to epilepsy centers and patient advocacy groups interested in following IOM recommendations to expand epilepsy self-management programs. We found that epilepsy self-management interventions varied widely in duration, format, and resource requirements. While no intervention demonstrated improvements in medication adherence or self-reported seizure frequency, limited data suggested the psychoeducational programs PACES and MOSES improved self-management skills in people with epilepsy. These group-based programs provided 10–16 hours of in-person training and were delivered by clinicians and/or peers with special training in epilepsy self-management. Implementing programs such as these in VHA would require considerable resources in the form of dedicated clinical staff, trained peer leaders, and identified meeting space. There also may be too few patients to efficiently form groups outside of urban centers or VA Epilepsy Centers of Excellence (ECoE).

The VA ECoE is a network of 16 Centers that provide comprehensive care to Veterans with seizure disorders. These Centers have adopted quality measures addressing self-management through their implementation of the Quality Indicators in Epilepsy Treatment (QUIET) tool.^81^ The QUIET measure set includes medication compliance assessment/enhancement and annual screening of self-management skills (side effect monitoring, contraception, mood disorders, lifestyle triggers, safety). Uniform clinical templates are available to address some of these measures, but individual ECoE sites and providers have flexibility in implementation, and patient education approaches are not standardized.

Our review addressed outcomes important to decision-making but should be considered as only one input into any decision about implementing and adopting self-management interventions that provide education and support more broadly for patients with epilepsy and their caregivers. Other outcomes, such as effects on patient experience and emotional well-being, may be important. Resources required to implement effective programs, whether to provide services to all or targeted to patients with epilepsy, and competing quality improvement initiatives should be considered. If the VHA were to move to implement and adopt self-management services for patients with epilepsy through the ECoE network or more broadly through PACT, our description of intervention components and synthesis of implementation and adoption barriers and facilitators could inform that effort. Clinician interventionists would benefit from intervention-specific training, dedicated time, and appropriate funding dedicated to providing self-management education and support, as opposed to layering on intervention responsibilities as a marginal service. Intervention materials should be personalized to the individual patient with epilepsy and include written information, and should be available before, during and after intervention sessions. A greater emphasis on goal-setting,^82^ a core feature of behavioral change interventions, should be considered. Delivery methods may vary, but should include consideration for web or app-based interventions^83^; if delivery is face-to-face with a clinician interventionist, dedicated space and salary support should be addressed. Introducing new care approaches into clinical care is often challenging. However, the VHA is uniquely situated to take on this challenge through the Quality Enhancement Research Initiative (QUERI) program,^84^ whose mission is to advance implementation science and identify effective strategies for implementing effective interventions.

The studies included in this review varied widely in their design, statistical analysis, and reporting. We highlight the most recent study included in the review, the SMART intervention by Sajatovic and colleagues, as an example of a well-structured and -reported study. Notable features of this study were the inclusion of Veteran populations, the inclusion of health care utilization and safety outcomes which were not reported in other studies we reviewed, and reporting that was transparent and amenable to meta-analysis. Future investigators should consider the SMART trial as a model for study design and sources of research support could use it as a guide for funding subsequent work in epilepsy self-management.

## Limitations

Our review benefited from being protocol driven, leveraging input from an expert panel, using a conceptual model, conducting an updated literature search that identified recent studies not included in prior reviews, using rigorous qualitative methods for analyzing barriers and facilitators to implementation and adoption, and using a detailed approach to categorizing and defining self-management intervention components. Despite these strengths, limitations in our approach and the primary literature remain. For example, we excluded studies that required a depression diagnosis or elevated depressive symptoms for enrollment, and thus studies with a depression-specific focus (eg, Project Uplift^85^) were excluded. Other limitations are detailed below.

### Publication Bias

Given the small number of studies, statistical methods to detect publication bias are not useful. Other strategies, such as searching ClinicalTrials.gov for completed but unpublished studies is not a particularly effective way to identify publication bias.^86^ Thus, although no publication bias was detected, tools for detection are poor.

### Study Quality

We were also limited by the existing literature. We identified relatively few studies, most with enrollment of fewer than 100 patients, and most were assessed as unclear or high ROB. Inadequate or unclear allocation concealment, incomplete outcome data, and outcome assessments that were not clearly blinded to intervention assignment contributed to judgments of higher risk. Interventions were often described incompletely. Intervention fidelity was often not reported; for many of the psychosocial therapy interventions, an educational component was only inferred, not described explicitly. Some outcomes of interest, such as effects on employment or workplace productivity and health care utilization were not reported. Other self-reported outcomes, in particular seizure rates, are difficult to measure. The tools used to assess the risk of bias for the studies included in KQ 3 did not allow for the calculation of summary scores. However, we assessed all studies for ROB. Of the 13 studies included in KQ 3, only 1 exhibited a high ROB due to insufficient information about ethical concerns, lack of rigorous analysis of study findings, and no clear value of the research. The remaining KQ 3 studies exhibited either low or unclear ROB.

### Heterogeneity

Self-management is a complex intervention, and these types of interventions make synthesis challenging. We compared interventions that varied in study design, intervention approaches, and patients enrolled. We addressed this diversity, in part, by separately analyzing randomized and nonrandomized trials and by considering intervention category. We described, but did not address quantitatively, variability due to differences in intervention designs such as intensity, delivery mode, and goals. Despite variability in intervention design characteristics, effects on most outcomes were consistent. For the studies in KQ 3, we addressed the inherent diversity by identifying the respondent (eg, patient with epilepsy, caregiver, or clinician) and then synthesizing emerging themes within ecological levels.

### Applicability of Findings to the VA Population

Only 1 of the included studies was conducted in the VHA or specifically with Veterans. However, we limited eligibility to studies conducted in OECD countries, which improves applicability to VHA. All intervention studies were conducted in North America, Europe, or Australia. Identified studies included predominantly white samples, and mid-life patients (median age 40) in contrast to the >50% of Veterans with epilepsy who are age 65 or older. Although this approach improved applicability of findings to Veterans, it means that potentially relevant studies conducted in non-OECD countries were excluded.

## Research Gaps/Future Research

We structure our reflection of gaps in evidence by considering each element of the PICOTS framework (Table 8). Although it would be possible to generate an extensive list of gaps in evidence, we restricted this list to the areas judged to be highest priority, given the current state of evidence. To facilitate future literature syntheses, we encourage investigators conducting clinical trials to include these studies in trial registries.

Table 8 Highest Priority Evidence Gaps

PICOTS Domain | Evidence Gap
Population | Research is needed with patients who are earlier in their course of illness and studies specifically focused on older adults with epilepsy. Evaluation of interventions and barriers/facilitators to implementation and adoption of selfmanagement interventions with Veterans and in large health systems is missing.
Interventions | - Self-management interventions are needed that incorporate patient, caregiver, and clinician interventionist input, account for cognitive limitations, incorporate peer support, and address other barriers to engagement and adherence.; - The role of technology (eg, smartphones, web-based support) has not been well studied in patients with epilepsy.; - Patients with epilepsy expressed a desire for an intervention team composed of a person with epilepsy and a clinician interventionist to provide selfmanagement education and support. Future research should further examine the composition of this interventionist dyad and identify who the clinician interventionist should be (eg, registered nurse, advanced practice registered nurse, physician, physician assistant).; - Future research should focus on the extent to which these intervention components (eg, peer support), use of technology, and other identified barriers/facilitators influence the person with epilepsy’s initial and sustained engagement in an epilepsy self-management program.
Comparators | Active controls, including usual care, are appropriate and should be described carefully.
Outcomes | - With the exception of quality of life, outcome measures varied greatly across studies, making synthesis difficult.; - Research is needed on outcomes most valued by patients with epilepsy, and how to best measure these outcomes.; - Future research is needed that specifically addresses the implementation and adoption of epilepsy self-management programs, as there may be additional personal, program, and site/system level barriers that need to be identified and addressed.
Timing | Self-management skills can take time to master and may take longer for patients with cognitive difficulty. Studies varied greatly in the timing of outcomes assessments. Consensus, or research, on the time required to acquire selfmanagement skills and the time required for new skills to potentially improve clinical outcomes should inform the timing of outcome assessments.
Setting | Few studies have examined interventions delivered outside of clinical settings. Future research should determine the preferred location for a self-management program for patients with epilepsy and their caregivers.

## Conclusions

Epilepsy is one of the most common chronic neurological conditions, with the potential to generate significant morbidity, impaired quality of life, socioeconomic decline, and high health care costs. Self-management is essential for patients who live with a chronic disease, and the VHA and other health systems are interested in offering self-management training to patients with epilepsy. In our protocol-based review, we found that tested interventions broke down into 2 categories: educational and psychosocial therapy interventions. These self-management interventions showed clinically important benefit for only a limited number of outcomes, but the confidence in these findings was mostly low. Further, there is unexplained variability in the effect of education interventions on quality of life and self-efficacy. Findings on facilitators and barriers to the implementation were stronger and point to a clearer path to the design and adoption of self-management interventions, including factors of patient personalization, information delivery, use of technology, and intervention personnel. Future research should be designed to address these implementation issues, and should include standardized outcome measures prioritized by patients and other stakeholders and Veteran populations.