# Results

## Organization of the Results

The results are organized to first report the yield of the literature search and the pattern of reported outcomes. Results are then reported for each KQ. For KQ 2, intervention effects are reported by category (eg, educational and psychosocial self-management interventions) and within the categories by primary and secondary outcomes.

## Literature Flow

We identified 2,535 studies through searches of MEDLINE^®^ (via PubMed^®^), Cochrane Central Register of Controlled Trials (CENTRAL), PsycINFO, and CINAHL (Figure 2). An additional 8 articles were identified through reviewing bibliographies of relevant review articles,^38–45^ for a total of 2,543 articles. After applying inclusion and exclusion criteria to titles and abstracts, 161 articles remained. Fifteen unique studies relevant to KQs 1 and 2 were retained for data abstraction, of which 13 were randomized and 2 were nonrandomized. Thirteen studies relevant to KQ 3 were retained for data abstraction. All studies were conducted in the United States, Canada, Europe, or Australia.

Appendix C presents detailed intervention characteristics, and Appendix D contains detailed study characteristics. Appendix E lists the excluded studies and reasons for exclusion. Appendix F contains a glossary of terms.

Figure 2 Literature Flow Chart

## Patterns of Outcome Reporting

With input from the TEP, outcomes were grouped into those for synthesis (primary, secondary outcomes) and those for which the frequency of reporting would be described. The primary and secondary outcomes are described in detail in KQ 2.

The pattern of outcomes identified for description but not synthesis is shown in Figure 3. Effects on psychological symptoms were reported frequently. Effects on health care utilization and work outcomes (eg, employment, productivity) were not reported.

Figure 3 Pattern of Outcome Reporting (15 Studies)

## KEY QUESTION 1 For adults with epilepsy, what are the most commonly employed components of self-management interventions evaluated in comparative studies?

### Key Points

- Self-management interventions used 2 approaches:
  ○ Educational interventions with content created specifically for patients with epilepsy (7 studies/interventions).
  ○ Psychosocial therapy interventions (eg, cognitive behavioral therapy [CBT], problem solving therapy [PST], progressive muscle relaxation [PMR]) established for other conditions and adapted for patients with epilepsy (8 studies/11 interventions).
- Both intervention approaches used a median of 4 self-management components:
  ○ All addressed education, implicitly or explicitly.
  ○ Most also addressed these components: stimulation of independent sign/symptom monitoring; enhancing problem-solving and decision-making skills for medical treatment management; and changing physical activity, dietary, and/or smoking behaviors.
- Studies delivered 4–16 hours of educational training. One study used self-paced internet-delivered modules, but most studies delivered the intervention face-to-face. Caregivers or family members were included in a minority of studies.
- Within educational interventions, 1 study explicitly provided a web-based forum for peer support, and 3 studies included peers as group leaders. Of the psychosocial therapy interventions, 3 utilized group sessions but did not clearly describe the facilitation of peer support, although it potentially could have occurred.
- Goal-setting with patients was present in only 3 educational interventions but present in 6 psychosocial therapy interventions across 5 studies.

### Detailed Findings

We identified 15 studies that met our inclusion criteria^46–60^ and mapped them to the 6 components described in the operational definition: (1) knowledge acquisition, (2) stimulation of independent sign/symptom monitoring, (3) medication management, (4) enhancing problem-solving and decision-making skills for medical treatment management, (5) safety promotion, and (6) changing physical activity, dietary, and/or smoking behaviors. Because some studies had more than 1 active intervention arm, a total of 18 intervention arms are described across the 15 studies. There was a median of 4 self-management components per intervention arm (range 2–6; Table 2). Medication management and safety promotion were the least frequently addressed components. (Refer to Appendix C for detailed intervention characteristics and Appendix D for study characteristics.)

Table 2 Components Across the 15 Studies (18 Intervention Arms)

Study Acronym Design | Knowledge | Symptom Monitoring | Medication Management | Problemsolving | Safety | Health Behaviors | Total Components
Educational Self-management Interventions
DiIorio, 2011^47^; WebEase; Randomized | Y | Y | Y | Y | N | Y | 5
Fraser, 2015^48^; PACES; Randomized | Y | N | Y | Y | N | Y | 4
Helgeson, 1990^51^; SEE; Randomized | Y | N | Y | Y | N | N | 3
May, 2002^53^; MOSES; Randomized | Y | Y | Y | Y | N | N | 4
Ridsdale, 2018^57^; SMILE-UK; Randomized | Y | Y | N | Y | Y | Y | 5
Sajatovic, 2018^58^; SMART; Randomized | Y | N | Y | Y | N | Y | 4
Gunter, 2004^60^; Nonrandomized | Y | Y | N | N | N | N | 2
Psychosocial Therapy Self-management Interventions
Caller, 2016^46^; HOBSCOTCH; Randomized
Arm 1 | Y | N | N | Y | N | Y | 3
Arm 2 | Y | N | N | Y | N | Y | 3
Gandy, 2014^49^; Randomized | Y | Y | Y | Y | N | Y | 5
Haut, 2018^50^; Randomized | Y | Y | N | N | N | Y | 3
Leenen, 2018^52^; ZMILE; Randomized | Y | Y | Y | Y | Y | Y | 6
McLaughlin, 2011^54^; Randomized
Arm 1 | Y | Y | Y | Y | N | Y | 5
Arm 2 | Y | Y | N | N | N | Y | 3
Puskarich, 1992^55^; Randomized | Y | N | N | N | N | Y | 2
Tan, 1986^56^; Randomized | Y | Y | N | Y | N | Y | 4
Gillham, 1990^59^; Nonrandomized
Arm 1 | Y | Y | N | Y | N | Y | 4
Arms 2 & 3^a^ | Y | Y | N | Y | N | Y | 4
Total arms | 18 | 12 | 8 | 14 | 2 | 15

a Arms 2 and 3 were assigned the same intervention in the initial intervention period of this crossover study.

In examining the components of each self-management intervention, we identified 2 distinct groups of interventions classified by emergent criteria: intervention focus (educational vs psychosocial therapy) and intervention development (created vs adapted for patients with epilepsy). The first group evaluated interventions that were created for patients and distinguished by a primary focus on education (Figure 4). Seven studies described explicit educational components with the implicit understanding that education may lead to skill acquisition.^47,48,51,53,57,58,60^ The second group focused on skill acquisition and evaluated interventions adapted for patients from previously existing therapies (Figure 4). Eight studies examining a total of 11 interventions described explicit skills acquisition components from therapeutic techniques; education components were described explicitly in some studies but in others were implicit.^46,49,50,52,54–56,59^ Within each of these groups of interventions, however, there was also diversity of duration and/or intensity of the intervention, composition and training of the intervention delivery team, mode(s) of delivery for the intervention, target(s) of the intervention, and components of self-management addressed (Figure 5).

Figure 4 Components Addressed in Self-management Interventions

Figure 5 Intervention Delivery Mode and Duration

### Educational Self-management Interventions Created for Patients with Epilepsy

Techniques used in educational self-management interventions included presentation of modules and didactic discussions aimed at increasing knowledge around the symptoms, triggers, and psychological, social, and vocational problems that often arise with epilepsy. Modules also often addressed coping skills, problem-solving skills, self-monitoring skills, and medication management skills that can be helpful for patients. One study explicitly discussed safety concerns related to physical harm.^57^ Five studies explicitly discussed symptom or seizure tracking, but only 2 had participants actively engage in this tracking through some form of diary or log. Only 3 studies incorporated some form of goal-setting with patients.^47,48,58^

Intervention duration varied considerably, with 2 interventions presenting durations that did not specify an amount of time because the intervention was a self-paced internet-delivered set of modules^47^ or reported simply as 2 days of intervention for an unspecified number of hours.^51^ The remaining intervention durations were generally 16 hours over 2 consecutive days, except for 2 interventions of 8 weekly sessions that varied from 60 to 90 minutes.^48,58^ Interventions were primarily in-person, group-based didactic instruction and presentation; however, 1 study was delivered solely through asynchronous internet media,^47^ 1 study began in-person and shifted to internet-based group didactic instruction and presentation, and 1 study was almost exclusively based on educational materials given to the patient within the context of a quality improvement intervention.^60^ Intervention providers were not always specified but generally were either peers with epilepsy or a nurse practitioner, both with specific intervention training. Interventions were targeted to patients, but in 3 studies involving group intervention, caregivers and/or family members were allowed to attend sessions.^51,53,57^ In addition to providing resources and education to patients, 1 intervention was developed to increase resources and education for practitioners providing care to patients.^60^ Peer support was present in 3 studies, 2 of which involved trained peers as group facilitators,^48,53,58^ and 1 of which involved discussions in online peer forums.^47^

### Psychosocial Therapy Self-management Interventions Adapted for Patients with Epilepsy

Techniques used in psychosocial therapy self-management interventions adapted for patients included broad multicomponent therapies, such as PST, CBT alone or paired with specific behavioral activation component or hierarchical stress inoculation, and “proactive coping skills” noted as being based on CBT principles. Some interventions used more specific techniques, such as PMR, cognitive training, and “brief psychological interventions” for problems like anxiety and depression. Six studies (7 interventions) evaluating psychosocial therapies also explicitly included some form of symptom or seizure monitoring.^49,50,52,54,56,59^ Five studies explicitly discussed goal-setting with patients.^46,49,52,55,56^

Intervention duration varied between a total of 4 hours and 16 hours, with the majority of interventions comprising some form of weekly treatment with daily at-home practice of some skills. No intervention consisted of fewer than 4 independent contacts for treatment. Additionally, the most common mode of treatment was in-person group sessions but often included some form of asynchronous technological support (eg, seizure diary smartphone application or audiotape) to aid in independent practice of self-management. For 5 of the studies the delivery team comprised some form of nurse practitioner or psychologist (including psychological interns). One study noted a “therapist” delivered the intervention but did not specify further. The delivery team was not specified for 2 studies. The stated target for each of the interventions was patients with epilepsy. Two additional studies allowed caregivers and/or family members to attend sessions^52^ or aid in identifying psychiatric/social issues for treatment.^59^ Peer support features were not explicitly discussed in any intervention. However, 3 interventions involved group therapy, which could have facilitated peer support.^52,54,56^

### Summary of Findings

Overall, self-management interventions descriptively appeared to fall into 2 major categories: educational content created for patients with epilepsy or established psychosocial therapy interventions adapted for patients with epilepsy. Interventions had a median number of 4 self-management components, and this number did not differ between educational and psychosocial therapy intervention categories. The number of components ranged from 2 to 6. Interventions were generally of moderate intensity, ranging from 4 to 41 hours. However, the delivery of equally intense interventions varied; for example, 16 hours of intervention could have occurred in either 2 consecutive 8-hour days, or eight 2-hour sessions spread over 8 weeks. Peer support and family involvement were minimally present. Goal-setting with patients was frequently present in psychosocial therapy interventions, but infrequently present in educational interventions.

## KEY QUESTION 2 What are the effects of self-management interventions on self-management skills and self-efficacy, clinical outcomes, and health care utilization?

### Key Points

- Educational self-management interventions:
  ○ Primary outcomes: Interventions may improve the use of self-management practices, but the certainty of evidence (COE) is low; there was no effect on overall QOL (low COE) or seizure rates (moderate COE).
  ○ Secondary outcomes: There was no effect on self-efficacy, social function, or medication adherence.
- Psychosocial therapy self-management interventions:
  ○ Primary outcomes: Interventions had a positive effect on overall QOL (low COE) but no benefit on seizure rates (low COE); evidence was insufficient to determine effects on self-management practices.
  ○ Secondary outcomes: Sparse data suggest a possible benefit on self-efficacy; there were inconsistent effects on social function and limited data for no effect on medication adherence.
- One study of a group-based intervention in high-risk patients found no effect on the combined outcome of emergency department visits or hospitalizations. No studies reported effects on workplace productivity or employment status.
- Only 1 study reported enrolling Veterans.

### Detailed Findings

We identified 13 randomized^46–58^ and 2 nonrandomized studies^59,60^ (2,514 patients) that evaluated self-management interventions for patients with epilepsy. Most studies enrolled mid-life adults with at least some college education. Health literacy was not reported by any study. The median time since diagnosis of epilepsy was 18 years; focal epilepsy was the most common type. Over one-half of studies were conducted in the United States, and only one enrolled Veterans. Self-management was compared with usual care, waitlist, or attention controls in all but 1 randomized study, a study that compared 2 therapy interventions. The 2 nonrandomized studies utilized a crossover design to compare 2 therapy interventions,^59^ and a cluster design to compare a quality improvement program with prominent educational features to usual care.^60^ The risk of bias (ROB) for patient-reported outcomes was judged low for 3 studies,^50,52,57^ unclear for 3 studies,^48,54,58^ and high for 9 studies.^46,47,49,51,53,55,56,59,60^ Table 3 shows the evidence profile for the studies. Detailed study characteristics are reported in Appendix D.

Table 3 Evidence Profile for Studies of Self-management Interventions for Epilepsy (n=15)

Number of studies: 13 randomized; 2 nonrandomized; Study years: 1986 to 2018; Number of patients, total enrolled (range): 2,514 (30–747); Women, median (range): 63% (51–74); Race/ethnicity: 72% white; not reported in 9 studies; Age, median (range): 41 (32–68); Education, median (range): 52% any college or above (15–77); not reported in 6 studies; Epilepsy duration, median (range): 18 years (13–27); not reported in 4 studies; Refractory epilepsy: 3 studies; Countries: Australia, Austria, Canada, Germany, Netherlands, Switzerland, United Kingdom, United States; Comparator: Usual care, waitlist, or attention (13 studies); active (2 studies); Risk of bias, patient-reported outcomes: 3 low, 3 unclear, 9 high

### Educational Self-management Interventions Created for Patients with Epilepsy

#### Primary Outcomes

##### Self-management

Four randomized studies reported the effects of educational self-management interventions on self-management behaviors using the Coping With Epilepsy and Adaptation scale or the Epilepsy Self-Management Scale. Three studies provided sufficient information for meta-analysis.^48,53,58^ These studies showed a moderate increase in self-management behaviors at 6-month follow-up (SMD 0.52; 95% CI 0.0 to 1.04; Figure 6). Intervention effects were consistent across studies (Q=2.8; p=0.24; I^2^=29.8%). The fourth study documented a nonsignificant P value for improvement in self-management but did not offer further statistics and had a high ROB.^47^ Overall, educational interventions created for patients with epilepsy suggest a possible benefit for self-reported measures of self-management and were judged at unclear or high ROB.

##### Quality of Life

Four randomized studies and 1 nonrandomized study reported effects on QOL using the 10- or 31-item versions of Quality of Life in Epilepsy Inventory (QOLIE). The QOLIE overall score is calculated as a weighted average of 7 multi-item subscales and standardized to a 0–100 point total score; the minimum clinically important change has been reported as 11.8.^61^ Three randomized studies provided sufficient data to summarize intervention effects (Figure 6). Overall, these 3 randomized studies showed no benefit on QOL (SMD 0.17; 95% CI −0.57 to 0.91), although there was heterogeneity in intervention effects across studies (Q=5.1; p=0.037; I^2^=60.8%). Both the larger low ROB study^57^ and a small, unclear ROB study,^50^ showed no intervention effect. A recent trial examining the novel SMART intervention showed a statistically significant improvement in quality of life over the 6 month study period (SMD 0.53; 95% CI 0.93 to 0.14),^58^ a marked divergence from the other randomized education trials. A fourth large, high ROB study examined a web-based educational intervention and reported no effect on QOL (p=nonsignificant), but did not provide sufficient data to calculate an intervention effect.^47^ An additional nonrandomized cluster study examined the effects of an educational intervention delivered within the context of a quality improvement study.^60^ This large, high ROB study reported small improvements in QOL (£1.5 points) in the intervention and control arms that did not differ between groups (mean difference [MD] 0.5; 95% CI −6.4 to 7.4).

##### Seizure Rates

Four randomized studies reported intervention effects on self-reported seizure rates using multi-item scales, self-reported seizure count, a categorical measure, or an unspecified self-report method.^51,53,57,58^ These studies, with mixed ROBs, demonstrated no impact of the group-based educational interventions on seizure frequency (SMD 0.0; 95% CI −0.03 to 0.04; Figure 6). Results were consistent across studies (Q=0.1; p=1.00; I^2^=0.0%), and the confidence interval for the summary SMD excludes even a small clinically important effect.

Figure 6 Effects of Educational Self-management Interventions on Primary Outcomes

Abbreviations: CI=confidence interval; ROB=risk of bias; SD=standard deviation; SMD=standardized mean difference

Table 4 shows the COE for educational self-management interventions created for patients with epilepsy.

Table 4 Certainty of Evidence for Educational Self-management Interventions Created for Patients with Epilepsy

Outcome | Number of Studies (Patients) | Findings | Certainty of Evidence (Rationale)
Epilepsy self-management | 4 randomized (569) | SMD 0.52 higher; (0 to 1.04 higher) | Low certainty of improved self-management; (rated down for serious ROB and reporting bias)
Quality of life | 4 randomized (492) | SMD 0.17; (0.57 lower to 0.91 higher) | Low certainty for no effect; (rated down for inconsistency and imprecision)
Quality of life | 1 nonrandomized (747) | MD 0.5; (6.4 lower to 7.4 higher) | Low certainty for no effect; (rated down for inconsistency and imprecision)
Seizure rates | 4 randomized (787) | SMD 0.00; (−0.3 lower to 0.04 higher) | Moderate certainty for no effect; (rated down for serious ROB)

Abbreviations: MD=mean difference; NR=not reported; SMD=standardized mean difference; ROB=risk of bias

#### Secondary Outcomes

##### Self-efficacy

Four group-based educational self-management studies addressed self-efficacy at intervals between 2–12 months’ follow-up.^48,51,57^ Overall, interventions did not improve self-efficacy (SMD 0.18; 95% CI −0.32 to 0.69). However, intervention effects varied significantly (Q=8.0; p=0.045; I^2^=62.7%). Studies varied importantly in timing of the outcome assessment (8 weeks to 12 months), which may be related to variable treatment effects. The one study showing moderate benefit delivered a stakeholder-informed, group-based intervention to patients (including veterans) at high risk for poor outcomes.^58^ A fifth study (WebEase) that delivered the educational intervention online reported effects on self-efficacy as “p=NS” and could not be included in the meta-analysis.^47^

##### Social Function

Effects of educational self-management interventions on social function were reported in 3 randomized studies^48,51,53^ and 1 nonrandomized study.^60^ Compared with controls, there were no effects of group-based self-management interventions on social function in randomized studies at 4–6 months follow-up (SMD −0.05; 95% CI −0.62 to 0.53; Figure 7). The nonrandomized study examined the effects of an educational intervention delivered within the context of a quality improvement study and reported no improvement on social function.

##### Medication Adherence

Two educational self-management studies reported effects on medication adherence using self-report measures. Neither a web-based intervention (WebEase),^47^ nor an in-person educational intervention (SMILE-UK)^57^ improved medication adherence assessed at 6 weeks (SMD 0.05, 95% CI −0.32 to 0.43) and 12 months (SMD 0.0, 95%CI −0.22 to 0.22; Figure 7) respectively. A third randomized study, evaluated the Sepulveda Epilepsy Education program and inferred drug adherence based on antiepileptic drug levels at 4 months’ follow-up.^51^ Drug levels were significantly higher in the intervention group, but assessment of this outcome varied across treatment arms (85% vs 50%), which may have biased the results.

##### Emergency Department Visits and Safety

One education-based self-management study evaluated emergency department and hospital utilization.^58^ The SMART intervention study reported 6-month changes in a composite measure of negative health events (seizures, emergency department visits, and hospitalizations) and emergency department visits or hospitalizations. Hospitalizations included all-cause admissions. Negative health events decreased more in the SMART education intervention group (mean change −10.16, SD 39.2) compared to waitlist control (mean change −1.93, SD 18.6; p = 0.04), but there was no significant improvement in emergency department and hospital utilization (p = 0.69).

Figure 7 Effects of Educational Self-management Interventions on Secondary Outcomes

Abbreviations: CI=confidence interval; N=study sample size; ROB=risk of bias; SD=standard deviation; SMD=standardized mean difference

### Psychosocial Therapy Self-management Interventions Adapted for Patients with Epilepsy

#### Primary Outcomes

##### Self-management

No studies of psychosocial therapy self-management interventions reported effects on self-management skills.

##### Quality of Life

Three studies reported the effects of psychosocial therapy interventions on QOL; all measured QOL with the QOLIE. Studies evaluated problem-solving therapy with or without cognitive training,^46^ CBT,^49^ and a multicomponent self-management intervention (ZMILE) with an emphasis on self-management skills building and skill practice.^52^ A larger, low ROB study showed small improvements in QOL at 3 and 6 months, but the confidence interval included no effect (MD 4.10; CI-1.12 to 9.32).^52^ Two smaller, high ROB studies reported improvement in QOL. The first was an 8-week study with intensive (5 times per week) patient contact (MD 7.20; CI 0.37 to 14.03; Figure 8).^46^ The second evaluated the effects of individual CBT on QOL at 2 and 3 months post-treatment and found a clinically important improvement in QOL at 3 months, though with a broad confidence interval (MD 11.98; CI 3.16 to 20.80, Figure 8).^49^ The meta-analysis shows a likely positive effect for psychosocial therapy interventions on quality of life, but confidence intervals were broad and risk of bias was high.(MD 6.64; CI 2.51 to 10.77; Q=2.3; p=0.31; I^2^=14.3%). A sensitivity analysis that adjusts the standard errors for small study effects resulted in a confidence interval that included no intervention effect (95% CI −2.45 to 15.73).

##### Seizure Rates

Three randomized studies and 1 nonrandomized study compared the effect of interventions to controls on seizure rates. The first, a small, low ROB study found no effect for progressive muscle relaxation compared to control at 3-month follow-up (SMD 0.06; 95%CI −0.43 to 0.55; Figure 8), though it did demonstrate a significant improvement from baseline rates.^50^ A second small study also examined progressive relaxation training.^55^ This high ROB study also demonstrated improvement in seizure rates from baseline for the intervention group, but no significant difference in average seizures when compared to control (SMD 0.47; 95% CI −0.35 to 1.28; Figure 8). Excluded from the forest plot because of insufficient data was a third small, high ROB trial that compared CBT with supportive counseling and waitlist control.^56^ The study reported improvement with the therapy intervention (50% of patients in the CBT group failed to improve, vs 80%-89% of patients in the supportive counseling and control groups) that did not reach statistical significance. A single nonrandomized crossover study examining 2 psychosocial therapy interventions identified similar improvements in seizure rates from baseline to Week 42 regardless of the intervention or order of intervention.^59^

An additional small randomized study compared CBT with a relaxation therapy control.^54^ We considered the relaxation arm an active intervention. The study, with unclear ROB, reported a significant improvement in seizure control in the CBT group versus relaxation control (Cohen’s D 0.63; p <0.01), and further noted a time-dependent increase in the improvement in the CBT group over the 3-month follow-up period. Overall, these small studies evaluating psychosocial therapy self-management interventions did not show benefit on seizure rates when compared with control or another active intervention.

Figure 8 Effects of Psychosocial Therapy Self-management Interventions on Primary Outcomes

Abbreviations: CI=confidence interval; N=study sample size; ROB=risk of bias; SD=standard deviation; SMD=standardized mean difference

Table 5 shows the COE for psychosocial therapy self-management interventions adapted for patients with epilepsy.

Table 5 Certainty of Evidence for Psychosocial Therapy Self-management Interventions Adapted for Patients with Epilepsy

Outcome | Number of Studies (Patients) | Findings | Certainty of Evidence (Rationale)
Epilepsy self-management | None | Not applicable | Insufficient
Quality of life | 3 randomized (187) | MD 6.64 higher; (2.51 to 10.77 higher) | Low certainty for improved quality of life; (rated down for serious ROB, imprecision)
Seizure rates | 3 randomized (106) | SMD range from 0.06 to 0.47 higher | Low certainty for no clinically important improvement; (rated down for serious ROB, imprecision)

Abbreviations: MD=mean difference; SMD=standardized mean difference; ROB=risk of bias

#### Secondary Outcomes

##### Self-efficacy

A single randomized study with low ROB reported the effects of a psychosocial therapy self-management intervention on self-efficacy.^52^ This multicomponent intervention showed a small to moderate improvement in self-efficacy (SMD 0.37; 95% CI −0.04 to 0.78) at 6-months follow-up, but the confidence interval includes no effect.

##### Social Function

Two small randomized studies with high ROB reported conflicting effects on social function. Compared with usual care, the HOBSCOTCH intervention using problem-solving therapy with or without cognitive training showed improved social function (SMD 1.08; 95% CI 0.47 to 1.69; Figure 9) at 8 weeks.^46^ In contrast, a small, high ROB study comparing CBT with supportive counseling and waitlist controls found no benefit on social function at 4-month follow-up (Figure 9).^56^ A third study that compared 2 active interventions, CBT plus education to relaxation therapy, found no differential effect on social function (SMD 0.15; 95% CI −0.79 to 0.50).^54^

##### Medication Adherence

Two studies reported effects on medication adherence using self-report measures. Neither a multicomponent self-management intervention^52^ nor a CBT intervention^56^ showed an effect on medication adherence at 4–6 months’ follow-up. However, both studies were relatively small and the confidence interval included the possibility of a moderate effect.

Figure 9 Effects of Psychosocial Therapy Self-management Interventions on Secondary Outcomes

Abbreviations: CI=confidence interval; N=study sample size; ROB=risk of bias; SD=standard deviation; SMD=standardized mean difference

### Effects of Interventions on Other Outcomes

None of the studies evaluating therapy-based self-management interventions reported effects on safety outcomes or emergency department visits related to epilepsy.

### Quality of Evidence for KQ 1 and KQ 2 Studies

For the 13 randomized studies, the ROB for patient-reported outcomes was judged low for 3 studies,^50,52,57^ unclear for 3 studies,^48,54,58^ and high for 7 studies.^46,47,49,51,53,55,56^ Objective outcomes (eg, emergency department visits) were not reported. Patterns that led to judgments of higher ROB included (1) inadequate or unclear allocation concealment (n=10), (2) incomplete outcome data (n=6), and (3) outcome assessments that did not clearly blind to intervention assignment (n=5). In addition to the lack of randomization for the 2 nonrandomized trials, unbalanced provider characteristics, incomplete outcome data, and possible selective outcome reporting led to a judgement of high ROB. ROB ratings for each study are shown in Figure 10 and the pattern of ROB assessments across studies in Figure 11.

Figure 10 Risk of Bias Ratings for the Included Studies^a^ a White indicates items that were not applicable. Blue/positive indicates items that were judged low ROB. Light gray/question mark indicates items that were judged unclear ROB. Dark gray/negative indicates items that were judged high ROB.

Figure 11 Risk of Bias Assessment Across Included Studies^a^ a White indicates items that were not applicable.

## KEY QUESTION 3 What are the identified facilitators and barriers that impact the adoption of self-management interventions for adults with epilepsy in large-scale health systems such as the VA?

### Key Points

- Involving patients with epilepsy in the development of interventions may facilitate implementation by ensuring that the self-management content is relevant to living with epilepsy.
- Tailoring intervention content to each individual patient may facilitate implementation.
- Patients may have cognitive limitations that present a barrier to intervention engagement and adherence.
- Technology use for self-management is highly dependent on individual characteristics such as familiarity with and ownership of technological devices (eg, mobile phones, computers). More research is needed to identify best practices for technology-based self-management interventions for patients.
- The role of the clinician (ie, the individual who interacts with the patient to provide self-management education and support) is important to the implementation of the intervention. The clinician should be appropriately trained, have the duties of the intervention incorporated into their dedicated clinical time, and be provided with clearly written, standardized protocols that articulate the clinician interventionist’s role in the intervention.
- No studies directly addressed facilitators and barriers to implementing and adopting self-management interventions for patients with epilepsy in the VHA or other large health systems.
- No studies directly enrolled Veterans with epilepsy.

### Detailed Findings

We present a summary of the studies, a description of identified themes across all studies, and the details for each theme organized by facilitators and barriers to implementation of self-management interventions. We identified 13 studies addressing facilitators and barriers to implementing self-management interventions for persons with epilepsy.^62–73^ The study designs in this analysis included semi-structured interview (n=5),^65,67–69,73^ cross-sectional survey (n=5),^64,70–72,74^ longitudinal survey (n=1),^63^ mixed-methods including group semi-structured interview, cross-sectional survey, and records review (n=1),^66^ and discrete choice experiment (n=1).^62^ Study respondents included patients with epilepsy, caregivers, and health care clinicians together,^63,64,66,68^ patients and caregivers only,^62,65,67,69,70,72,73^ and health care clinicians.^71^ No studies were completed at the VHA, and none purposely recruited Veterans with epilepsy or stated they included Veterans with epilepsy.

#### Ecological Levels

For each facilitator and barrier, we first identified the respondent (eg, the patient with epilepsy, caregiver, or health care clinician) associated with each theme. Then we examined each theme at 1 of 3 levels, adapted from ecological models of health behavior, which emphasize that determinants of behavior derive from individuals and characteristics of their environments that influence behavior directly and in interaction with one another.^36^

- Person level: Patient or caregiver who is engaging in the epilepsy self-management intervention
- Program level: Self-management intervention being implemented and evaluated
- Site/system level: Health care site or system where the self-management intervention is being implemented and evaluated

#### Themes

Thematic synthesis of the abstracted data identified 5 themes across all KQ 3 studies that could be applied conceptually to facilitators and barriers. Table 6 defines the themes and Table 7 shows the presence of themes by study.

Table 6 Themes Across Studies of Self-management of Epilepsy

Theme | Definition
Relevance | Relevance of intervention content or topics that facilitate the acquisition of self-management skills in patients with epilepsy
Personalization | Intervention components that account for the individual social, physical, and environmental characteristics of the patient
Intervention components | Components and dosing of the intervention
Technology considerations | Considerations that account for patient’s use of, familiarity with, and ownership of technology (eg, computers, laptops, mobile phones)
Clinician interventionist | Role and preparation of individual who leads the intervention, engages with the patient, and provides self-management education and/or support to the patient

Table 7 Presence of Themes by Study

Study | Facilitators | | | | | Barriers
| R | P | IC | TC | CI | R | P | IC | TC | CI
Atkinson-Clark, 2018^62^ | | | | | | | ✕ | ✕
Begley, 2015^63^ | | | ✕ | ✕ | | | | ✕
Buelow, 2001^73^ | ✕
Clark, 2010^71^ | ✕ | | | | | ✕ | ✕ | | | ✕
Fraser, 2011^72^ | ✕ | | ✕ | | ✕
Johnson, 2012^64^ | | | | | | ✕ | | | | ✕
Laybourne, 2015^65^ | ✕ | ✕ | ✕ | | | | | ✕
Leenen, 2016^70^ | | ✕ | | ✕ | | | ✕ | | ✕
Leenen, 2017^66^ | | | ✕ | | | ✕ | ✕ | ✕ | ✕ | ✕
Ridsdale, 2017^67^ | | | ✕ | | | ✕ | ✕ | ✕
Snape, 2017^68^ | ✕ | ✕ | ✕ | | | | | ✕
Walker, 2012^69^ | | ✕ | | | | | ✕
Begley, 2018^74^ | ✕ | | ✕ | ✕ | | | | | ✕

Abbreviations for themes (from Table 6): R=Relevance; P=Personalization; IC=Intervention components; TC=Technology considerations; CI=Clinician interventionist

### Facilitators

The presence of facilitators of epilepsy self-management interventions at any level (ie, person, program, site/system) was noted in 10 studies.^63,65–73^ Two studies did not include any facilitators.^62,64^

#### Relevance

At the person level, facilitators included the opportunity for the patient with epilepsy to acquire self-management skills and content that were highly applicable to living with epilepsy (eg, eliciting concerns about self-managing and daily living from the patient or caregiver)^68,71,74^ and the participant’s desires for obtaining self-management skills from the intervention.^73,74^ Facilitators at the program level included intentional programmatic features such as enabling the patient’s acquisition of skills for living with epilepsy, learning how to apply self-management skills and coping strategies in daily life, and communicating with family, caregivers, and health care clinicians about epilepsy.^65,68,72^ No relevance facilitators were identified at the site/system level.

#### Personalization

At the person level, facilitators included identifying whether the patient owned the necessary technology for the intervention (eg, computer, mobile telephone)^70^ and had an identified source of social support,^69^ and whether the intervention was congruent with the patient’s preference for peer support or group interaction.^65,68^ At the program level, facilitators included developing the intervention and tailoring its components to build on the current self-management practices of the patient.^70,74^ No personalization facilitators were identified at the site/system level.

#### Intervention Components

At the person level, facilitators included providing written materials (eg, educational content) to the patient or caregiver during and after the intervention.^68^ At the program level, facilitators included involving family members in the intervention,^66^ using an empowerment approach to help the patient develop self-management skills,^65,74^ the format of the intervention (eg, group format that included both the patient and caregiver),^68^ the ability to personalize materials to each patient,^68,72,74^ the availability of written materials,^63,65,68^ the ability to interact with a group,^66,67^ the provision of peer support,^66,67^ and the length and duration of the intervention sessions.^66,67^ At the site/system level, facilitators included developing intervention materials using uniform program standards to ensure program fidelity across intervention sites.^68^ One study indicated that the site of the intervention (ie, medical center) was unimportant, as patients with epilepsy indicated no preference of one site over another.^72^

#### Technology Considerations

At the program level, facilitators included the high level of usability of intervention components located on the internet, mobile applications, or phones.^63,70,74^ No technology facilitators were identified at the person or site/system levels.

#### Clinician Interventionist

At the program level, facilitators included creating an intervention team consisting of a patient in tandem with an expert health care clinician who could deliver the intervention content.^72^ No clinician interventionist facilitators were identified at the person or site/system levels.

### Barriers

The presence of barriers to epilepsy self-management interventions at any level was noted in 10 studies.^62–71^ Two studies did not include any relevant barriers.^72,73^ Stakeholders included clinicians, social service providers, and researchers,^71^ and patients and clinicians.^64^

#### Relevance

At the program level, barriers included incongruent responses between patients and clinicians about the patient’s problems and needs to be addressed in the epilepsy self-management program,^64^ incongruent opinions by clinicians, researchers, and social service providers on the necessary intervention content,^71^ incongruent responses between patients and clinicians on who should lead the intervention and provide epilepsy self-management education and support,^64^ educational content that was too general or lacking in personalization or tailoring to the patient, his or her disease state and relevant comorbidities,^64,67,74^ and not identifying what the patient views as important in self-management and living with epilepsy.^66^ No relevance barriers were identified at the person or site/system levels.

#### Personalization

At the person level, barriers included the patient’s memory and/or cognitive impairments,^62,64,67,68,70,71^ the patient’s disinterest in participating in a self-management intervention,^62^ not identifying the patient’s preference or desire for self-management support,^69^ and no current use of the technology by the patient.^70^ At the program level, barriers included not accounting for the cognitive limitations of patient.^67^ At the site/system level, barriers included not accounting for the characteristics of the patient population such as the patient’s access to health care^71^ or transportation concerns.^66^

#### Intervention Components

At the program level, barriers included requiring the patient to incur a cost for participating in the intervention,^62^ not identifying how demographics (eg, country of origin, burden of disease, socioeconomic status, level of activation) influence the patient’s participation and views of the intervention,^62^ not identifying the ideal time for follow-up by the clinician after the intervention,^66^ not having clear instructions for the role of caregivers participating in or affected by the intervention,^66^ not having written materials (eg, program manuals, handouts, website resources) the patient can refer to during and after the intervention,^65,66^ having groups heterogeneously composed of individuals with disparate experiences of living with epilepsy,^67^ experiencing challenges to scheduling group intervention sessions because of calendar conflicts for participants and clinicians,^68^ and not identifying the optimal duration and length of the intervention for patients.^62,65,67^ Barriers at the site/system level included having different levels of attrition at study sites^63^ and challenges to using a participatory approach to intervention development and content identification (eg, lengthy time to complete, need to obtain ethical approval, and efforts to ensure participant engagement).^68^ No intervention component barriers were identified at the person level.

#### Technology Considerations

At the person level, barriers included the patient’s lack of knowledge about eHealth tools and functions, having concerns about the privacy of eHealth tools, and varying individual preferences for using technology for epilepsy self-management.^70^ At the program level, barriers included difficulty developing eHealth tools with high usability, and a lack of help for users encountering technical difficulties.^66,70,74^ At the site/system level, barriers included not acknowledging or addressing the inequity of access to eHealth tools within the sample or the person with epilepsy’s concerns about the privacy of eHealth tools.^70^

#### Clinician Interventionist

At the program level, barriers included not incorporating the duties of the intervention into the clinician interventionist’s normal job duties,^66^ not adequately preparing the clinician interventionist to deliver the intervention content,^66^ developing a complex intervention protocol that is difficult to deliver,^66^ and not identifying the optimal professional role and educational training of the clinician interventionist.^64,71^ At the site/system level, barriers included a lack of opportunity for the clinician interventionist to engage in continuity of care for the person with epilepsy following the conclusion of the intervention,^66^ and not accounting for the limited time allotted for medical visits.^71,74^ No clinician interventionist barriers were identified at the person level.

### Quality of Evidence for KQ 3 Studies

The tools used to assess risk of bias (ROB) for the descriptive quantitative, mixed-methods, and qualitative studies did not provide for the calculation of summary scores for individual papers. Among the 7 descriptive quantitative studies,^62–64,70–72,74^ ROB was heterogeneous (Figure 12). Patterns that led to judgments of higher ROB included unclear representativeness of the sample (n=6),^62,64,70–72,74^ high (n=2)^64,71^ or unclear (n=4)^63,70,72,74^ ROB from non-response, unclear risk of bias in sampling strategy (n=3),^71,72,74^ and unclear appropriateness of measures (n=2).^71,74^

Figure 12 Risk of Bias Ratings for the Included Descriptive Quantitative Studies^a^ a Blue/positive indicates items that were judged low ROB. Light gray/question mark indicates items that were judged unclear ROB. Dark gray/negative indicates items that were judged high ROB.

The overall ROB in the 5 qualitative studies was low (Figure 13).^65,67–69,73^ However, we identified several concerning flaws in 1 study^73^ including insufficient information provided regarding ethical considerations or consideration of the relationship between the researcher and participants, a lack of rigorous analysis of study findings, and no description of the clear value of the research. We also identified 1 study that had unclear ROB regarding the relationship of the researcher to the participants.^69^

Figure 13 Risk of Bias Ratings for the Included Qualitative Studies^a^ a Blue/positive indicates items that were judged low ROB. Gray/question mark indicates items that were judged unclear ROB.

The ROB of the mixed-methods study was somewhat unclear, as it had no integration of its qualitative and quantitative findings (Figure 14).^66^

Figure 14 Risk of Bias Ratings for the Included Mixed-Methods Study^a^ a Blue/positive indicates items that were judged low ROB. Gray/question mark indicates items that were judged unclear ROB.