# Methods

We followed a standard protocol for this review. Each step was pilot-tested to train and calibrate study investigators. The PROSPERO registration number is CRD42018098604. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^25^

## Topic Development

This topic was nominated by the VA National Neurology Program Office in the Office of Specialty Care Services, which is responsible for policies and programs for neurological disorders in the VHA nationally. The review will be used to identify the current evidence base and its quality to support the use of self-management programs aimed at patients with epilepsy, and identify potential barriers in the adoption of these programs within the VHA system.

### Key Questions

The Key Questions (KQs) for this report were:

- KQ 1: For adults with epilepsy, what are the most commonly employed components of self-management interventions evaluated in comparative studies?
- KQ 2: What are the effects of self-management interventions on self-management skills and self-efficacy, clinical outcomes, and health care utilization?
- KQ 3: What are the identified facilitators and barriers that impact the adoption of self-management interventions in large-scale health systems such as the VHA?

### Conceptual Framework

Most clinical outcomes for chronic conditions are mediated by daily patient-initiated behaviors outside of the health care setting,^26^ underscoring the importance of developing effective self-management strategies. Following a review of self-management definitions, Jonkman and colleagues constructed an exact but flexible operational definition for self-management to maximize external validity without being overly restrictive.^27^ We adopted their operational definition for the current review with 2 modifications. To increase the breadth of eligible interventions, we required only 1 component beyond knowledge acquisition (instead of 2 components). We also specified that decision-making skills should be for epilepsy-relevant behaviors such as epilepsy treatment management, safety promotion (eg, driving,), and changing relevant health behaviors (including stress management, sleep, and substance use). Our modified operational definition follows:

Self-management interventions aim to equip patients with skills to actively participate and take responsibility in the management of their epilepsy in order to function optimally through knowledge acquisition and a combination of at least 1 of the following behaviors: stimulation of independent sign/symptom monitoring, medication management, enhancing problem-solving and decision-making skills for medical treatment management, safety promotion, and changing physical activity, dietary, and/or smoking behavior.

The conceptual model (Figure 1) outlines the population, intervention, outcomes, and potential effect moderators. The self-management interventions map to our modified definition but also include important contextual elements such as the delivery mode (eg, in-person, group, web-based), dose (eg, duration and frequency of contacts), and specific approaches used (eg, cognitive behavioral therapy). Potential effect moderators were identified based on patient characteristics that may be associated with different intervention effects.

Figure 1 Conceptual Model for Self-management of Epilepsy

## Search Strategy

In collaboration with an expert reference librarian, we conducted a primary search from inception through April 13, 2018, of MEDLINE^®^ (via PubMed^®^), Cochrane Central Register of Controlled Trials (CENTRAL), PsycINFO, and CINAHL. We updated the MEDLINE search on October 31, 2018. We used a combination of MeSH keywords and selected free-text terms (eg, epilepsy, self-management, self-care) to search titles and abstracts (Appendix A). We also conducted hand-searches of references from selected high-quality systematic reviews and exemplar studies identified during the topic development process and as identified by our stakeholders.

Our search strategy was informed by the Cochrane Effective Practice and Organization of Care (EPOC) Group.^28^ EPOC criteria were developed to capture both randomized and nonrandomized study designs. All citations were imported into 2 electronic databases (for referencing, EndNote^®^, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada).

## Study Selection

We used artificial intelligence (AI) technology developed as part of the DistillerSR software program (DistillerAI; Evidence Partners Inc., Manotick, ON, Canada) to assist with screening abstracts. Using prespecified inclusion/exclusion criteria (Table 1), the titles and abstracts of a subset of articles, enriched for potential relevance to the study questions (approximately 100) identified through our primary search and prior reviews, were classified independently by 2 senior investigators for relevance to the KQs. After resolving disagreements between the investigators, this set of included and excluded articles was used to train DistillerAI.^29^

DistillerAI was used to screen the remaining titles and abstracts using a “high confidence” approach that employs 2 algorithms to classify citations. All citations classified by DistillerAI with certainty (ie, eligible or ineligible) underwent abstract review by 1 investigator. All other citations (50%) underwent abstract screening by 2 investigators. Articles included by an investigator or AI algorithm underwent full-text screening by 2 investigators. Disagreements were resolved by consensus between the investigators or by a third investigator. Articles meeting all eligibility criteria were included for data abstraction.

Table 1 Eligibility Criteria

Study Characteristic | Include | Exclude
Population | - Adults (aged ≥18) with new or chronic epilepsy; - Family members and/or caregivers of those with epilepsy; - KQ 3 only: Stakeholders involved in implementation (eg, neurologists, health coaches, nurses, administrators) | - Children; - Populations with <70% adults; - Severe learning disabilities Non-epileptic seizures (ie, psychogenic seizures); - Populations who have been recruited for depression or who have major mental illness (eg, bipolar, major depressive disorder, schizophrenia)
Intervention | Self-management defined as interventions that aim to equip patients with skills to actively participate and take responsibility in the management of epilepsy in order to function optimally through at least knowledge acquisition and a combination of 1 or more of the following:; - Stimulation of independent sign/symptom monitoring; - Medication management; - Enhancing problem-solving and decision-making skills for epilepsy treatment management, safety promotion (eg, driving); - Changing health behaviors (including stress management, sleep, substance use)^a^; Examples include:; - Psychoeducation (eg, cognitive behavioral therapy); - Behavioral interventions (eg, adherence strategy training); - Personalized care plan development and coaching | - Multicomponent interventions that include self-management but where self-management is not the primary intervention; - Cognitive behavioral therapy focused on comorbid mental illness in patients with epilepsy (eg, depression in patients with epilepsy); - Education-only interventions; - General care delivery interventions (eg, introducing specialist nurse practitioner or implementation of clinical practice guidelines)
Comparator | Any (usual care, attention control, active intervention) | None
Outcomes | [underlined: Self-management skills/self-efficacy]; - Epilepsy self-efficacy and epilepsy selfmanagement scales^b^; - Medication adherence^b^; - Disease knowledge; [underlined: Clinical]; - Seizure rate/frequency/severity^b^; - Quality of life^b^; - Social function/engagement (eg, days work missed, or validated measure)^b^; - Psychological symptoms (ie, distress, depressive or anxiety symptoms); - Safety outcomes (eg, motor vehicle accidents)^b^; - Medication toxicity; [underlined: Health care utilization]; Acute care or emergency department visits, hospitalization, or outpatient specialty visits for epilepsy | None
Timing | KQ 1, KQ 2:; - Must be longitudinal (any length); - Assessments at end of treatment and longest follow-up | KQ 1, KQ 2:; Cross-sectional or assessments at the time of intervention delivery
Setting | - Delivered in person (individual or group) in outpatient settings, or remotely via telehealth technology (eg, mobile or internet); - Delivered by health care team members or trained layworkers | - Inpatient; - Delivered only in emergency departments
Design ^b^ | KQ 1, KQ 2:; - Randomized trials; - Nonrandomized trials; - Controlled before-after studies^c^; - Prospective cohort study if it includes a properly adjusted analysis; KQ 3:; - Above KQ study designs; - Qualitative and survey designs if specifically addressing facilitators and barriers to adoption of epilepsy selfmanagement interventions | KQ 1, KQ 2:; - Self-described pilot studies and/or sample size <20; - Studies with retrospective data collection; - Interrupted time series; - Case series; - Systematic reviews/metaanalyses; KQ 3:; - Reports that do not include primary data on barriers or facilitators
Language | English | Non-English
Countries | OECD^d^ | Non-OECD
Years | Any | None
Publication Types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

a Adapted from Jonkman et al, 2016.^27^

b Outcomes prioritized for synthesis. For other outcomes, only the frequency of reporting is described.

c See Cochrane EPOC criteria for definitions and details.28

d OECD = Organization for Economic Cooperation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

Abbreviation: KQ=Key Question

## Data Abstraction

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. Data elements included descriptors to assess applicability, quality elements, intervention/exposure details, and outcomes.

Key characteristics abstracted were patient descriptors (eg, age, sex, race, duration of epilepsy if available), intervention characteristics (eg, interventionist if targeting family member/caregiver, delivery modality, duration/intensity, key intervention components, peer support), comparator, and outcomes, as described previously. For studies relevant to KQ 3, we abstracted barriers (ie, description of themes or factors that impeded the use and implementation of the intervention as reported in the study’s results and/or findings sections) and facilitators (ie, description of themes or factors that aided the use of the intervention as reported in the study’s results and/or findings sections) to the implementation of self-management interventions (as distinct from barriers and facilitators of an individual engaging in self-management behaviors). In addition, we abstracted respondent characteristics (eg, if respondent was a patient with epilepsy, caregiver, or health care provider), and design details (eg, semi-structured interviews, cross-sectional surveys, open-ended questions). Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors. Key features relevant to applicability included the match between the sample and target populations (eg, age, Veteran status).

## Quality Assessment

Quality assessment was done by the investigator abstracting or evaluating the included article and was over-read by a second, highly experienced investigator. Disagreements were resolved by consensus between the 2 investigators or, when needed, by arbitration by a third investigator.

For KQ 1 and KQ 2, we used the Cochrane EPOC risk of bias (ROB) tool, which is applicable to randomized and nonrandomized studies.^28^ These criteria are adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; validity of outcome measures; protection against contamination; selective outcomes reporting; and conflict of interest. We assigned a summary ROB score (low, unclear, high) to individual studies separately for non–patient reported outcomes, hereafter referred to as objective outcomes (eg, emergency department visits), and patient-reported outcomes (eg, quality of life).

Summary ROB ratings are defined as follows:

- Low ROB: Bias, if present, is unlikely to alter the results seriously.
- Unclear ROB: A risk of bias that raises some doubts about the results.
- High ROB: Bias may alter the results seriously.

For KQ 3 qualitative studies, we utilized 3 ROB forms for different study designs. For qualitative studies (n=5), we adapted the 10-item Critical Appraisal Skills Programme (CASP) for Qualitative Research Studies.^30^ Each item is rated “Yes,” “No,” or “Can’t tell”; there is no summary rating. For the remaining studies, we adapted the Mixed Methods Appraisal Tool (MMAT).^31^ For the quantitative descriptive studies (n=7) we used the 5-item MMAT specific to quantitative descriptive studies. These criteria address the sampling strategy, the sample representativeness, measurements, risk of nonresponse bias, and appropriateness of the statistical analysis. For the mixed methods study (n=1), we used the 5-item MMAT specific to mixed methods studies. These criteria address the rationale for using mixed methods, the integration of the study components, the interpretation of the study components, discussion of divergences or inconsistencies between the quantitative and qualitative data, and how each component of the study adheres to the quality criteria of each of the quantitative and qualitative methods. The MMAT rates each item “Yes,” “No,” or “Can’t tell”; there is no summary rating. Details on quality assessment criteria are presented in the Glossary.

## Data Synthesis

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. We initially planned to classify studies into those meeting the full definition of self-management^27^ and those with fewer components. However, studies were classified more naturally into 2 categories, those emphasizing education and those emphasizing skill acquisition from psychosocial therapy approaches.

We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects (KQ 2). For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of results reporting. We aggregated outcomes when there were at least 3 studies with the same outcome, based on the rationale that 1 or 2 studies do not provide adequate evidence for summary effects. When quantitative synthesis was feasible, we stratified by study design (randomized vs nonrandomized) and by intervention category. Although we planned to evaluate the consistency of effects by components of the intervention, there were too few studies to perform these analyses.

When quantitative synthesis was possible, outcomes were summarized using the mean difference (MD) when all studies reported the outcome using the same scale (eg, quality of life), and standardized mean difference (SMD) for outcomes using different measures for the same construct (eg, medication adherence). The SMD is the difference in outcomes between the intervention and comparator, divided by the pooled standard deviation. Cohen suggested the following guidelines for interpreting the magnitude of the SMD: small = 0.2; medium = 0.5; and large = 0.8.^32^ For analyses with few (n <20) studies, we used the Knapp-Hartung approach^33^ to adjust the standard errors of the estimated coefficients. When intervention effects varied importantly across studies, we conducted a sensitivity analyses to omit studies judged to be at high risk of bias. We evaluated for statistical heterogeneity using visual inspection and Cochran’s Q and I^2^ statistics. Test statistics for publication bias (eg, Begg’s or Egger’s regression statistics) only perform adequately when there are more than 10 studies in an analysis. Since no analyses met this threshold, formal analyses for publication bias were not performed.

When quantitative synthesis was not feasible, we analyzed the data narratively. We gave more weight to the evidence from higher-quality studies with more precise estimates of effect. Qualitative synthesis focused on documenting and identifying patterns in efficacy and safety of the interventions across conditions and outcome categories. We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions.

For the KQ 3 analysis, we created a qualitative team composed of 2 co-investigators (AAL, AS) who had experience in qualitative methodology. Under the guidance of the primary investigator (JWW), the qualitative co-investigators led the abstraction and analysis of data collected for KQ 3. We analyzed the abstracted data from the KQ 3 studies using thematic synthesis and the framework method.^34,35^ Using the KQ 3 question as a guide, we created an a priori framework based on the ecological framework^36^ that included barriers and facilitators as reported for a category (eg, patient with epilepsy or caregiver; program or intervention; and site or health system). All abstracted findings were categorized; data could be in only 1 framework (eg, a facilitator or a barrier) and in only 1 category (eg, patient/caregiver, program/intervention, site/health system). We then completed first-level analysis of these data and confirmed the validity of our interpretations by referencing the original texts. After the data were independently coded and discussed among the 2 qualitative researchers, we conducted thematic synthesis by identifying and grouping related codes within each category (eg, patient/caregiver, program/intervention, site/health system). Then, each researcher independently organized related codes into themes. We reviewed the theme development and then identified overarching themes that applied to both facilitators and barriers. The creation and identification of codes and themes was iterative; to ensure rigor and validity of these findings, we independently coded and developed themes and then discussed theme development and identification until we reached agreement between the 2 researchers.

## Rating the Body of Evidence

The certainty of evidence (COE) for each KQ was assessed using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE).^37^ We limited GRADE ratings to those outcomes identified by the stakeholder and Technical Expert Panel (TEP) as critical to decision-making. In brief, this approach requires assessment of 4 domains: risk of bias (ROB), consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators as high, moderate, or low strength of evidence. In some cases, high, moderate, or low ratings were impossible or imprudent to make. In these situations, a grade of insufficient was assigned.

## Peer Review

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix B.