# Introduction

Epilepsy affects about 50 million people worldwide,^1^ with the highest rates in children and older adults. In VHA, an estimated 79,576 Veterans were treated for epilepsy in 2016; almost 50% were 65 years of age or older. In the Veteran population, there is a significant association with prior traumatic brain injury; this is of particular importance to Veterans serving in Operation Iraqi Freedom and Operation Enduring Freedom.^2^

Epilepsy may diminish quality of life even when seizures are controlled.^3–5^ Patients with epilepsy are at greater risk for mood disorders and have higher rates of injury and premature death than the general population. Sex-specific issues can complicate epilepsy care, such as interactions between antiepileptic drugs (AEDs) and contraceptive agents or management of teratogenic AEDs during pregnancy.^6,7^ Patients often face the challenges of low socioeconomic status along with high levels of perceived social stigma, creating financial and social barriers to care.^8^ Seizure control and medication adherence are common challenges among patients; decreased health care literacy, poor social support, burdensome side effects, low socioeconomic status, and cooccurring psychiatric disorders are all associated with lower medication adherence.^9–12^ Further, some epilepsies are associated with cognitive impairment or impulse-control issues, further complicating care plans. Patient self-management behaviors are very important to the management of epilepsy, as decreased patient participation in treatment regimens is a major cause of breakthrough seizures, leading to increased hospital utilization and mortality.^13,14^

In 2003, the Institute of Medicine defined self-management support as “the systematic provision of education and supportive interventions by health care staff to increase patients’ skills and confidence in managing their health problems, including regular assessment of progress and problems, goal setting, and problem-solving support.”^15^ Self-management support is a core component of care delivery models^16–18^ developed to improve chronic disease care, such as the patient-centered medical home,^19^ and is a requirement for participation in some Medicare alternative payment programs.^20^ In VA, self-management has an established role in the management of chronic conditions and is a core component of programs such as primary care–mental health integration and patient-aligned care teams.

Systematic reviews have shown that self-management support for patients with chronic illness improves symptoms and role function, but these positive effects are influenced by the type of chronic illness and self-management skills taught.^21–23^ Further, the effectiveness of self-management may be influenced by co-occurring conditions such as traumatic brain injury or depressive disorders, and by levels of education or health literacy. For patients with epilepsy, improved self-management skills could improve self-efficacy (an individual’s belief in his or her innate ability to achieve goals), medication adherence, avoidance of seizure triggers, and improve patient and family knowledge about when to seek urgent medical care. This represents a more holistic approach to chronic illness care than strategies such as patient education or reminders that focus solely on medication adherence. Self-management interventions hold promise for patients with epilepsy, although cognitive impairment and psychiatric disease that are frequently comorbid with epilepsy, along with the paroxysmal nature of seizures, may attenuate the effects of these interventions. A Cochrane review that included literature published through December 2013 evaluated self-management strategies for adults with epilepsy.^24^ The review identified only 4 trials and concluded that self-management education has some evidence of benefit but did not find clear evidence of substantially improved outcomes for adults with epilepsy.

The current review was requested by the VA National Neurology Program Office in the Office of Specialty Care Services, which is responsible for policies and programs for neurological disorders in the VHA nationally. The review will be used to identify the current evidence base and its quality to support the use of self-management programs aimed at patients with epilepsy, and identify potential barriers in the adoption of these programs within the VHA system. Prior systematic reviews on this topic were inadequate for the needs of our stakeholders because they did not include recent important studies; did not adequately consider components such as peer support, which has particular relevance to Veterans; and did not address implementation of self-management interventions.