# APPENDIX F Glossary

For full study citations in this appendix, please refer to the report’s main reference list.

Term | Definition
Certainty of evidence (COE) | We assessed COE using the Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach^37^ for 4 domains:
Certainty of evidence (COE) | Domain | Rating | How Assessed
Certainty of evidence (COE) | Risk of bias | Low; Unclear; High | Assessed primarily through study design and aggregate study quality
Certainty of evidence (COE) | Consistency | Consistent; Inconsistent; Unknown/NA | Assessed primarily through whether effect sizes are generally on the same side of “no effect,” the overall range of effect sizes, and statistical measures of heterogeneity
Certainty of evidence (COE) | Directness | Direct; Indirect | Assessed by whether the evidence involves direct comparisons or indirect comparisons through use of surrogate outcomes or use of separate bodies of evidence
Certainty of evidence (COE) | Precision | Precise; Imprecise | Based primarily on the size of the confidence intervals of effect estimates, the optimal information size and considerations of whether the confidence interval crossed the clinical decision threshold for using a therapy
Certainty of evidence (COE) | Summary COE ratings for a body of evidence:; - High—High confidence that the true effect lies close to that of the estimate of the effect.; - Moderate—Moderate confidence in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.; - Low—Limited confidence in the effect estimate. The true effect may be substantially different from the estimate of the effect.; - Very low—Very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.; - Insufficient—Impossible or imprudent to rate. In these situations, a rating of insufficient is assigned.
Cognitive behavioral therapy (CBT) | Psychological treatment that addresses unhelpful ways of thinking and unhelpful behavior.
Hierarchical stress inoculation | Technique used to systematically desensitize individuals to anxiety-producing situations through conceptualizing and coping with increasing stress.
Objective outcomes (ie, non–patientreported outcomes) | Measures that are not subject to a large degree of individual interpretation and are likely to be reliably measured across patients in a study, by different health care providers, and over time.
Patient-reported outcomes | Outcomes that are directly reported by the patient without interpretation of the patient’s response by a clinician or anyone else and pertains to the patient’s health, quality of life, or functional status associated with health care or treatment.
Problem solving therapy (PST) | Psychological treatment that teaches management of negative effects of stressful life events. Goals of PST include identifying types of stressors that trigger emotion and better understanding and management of negative emotions.
Progressive muscle relaxation (PMR) | A relaxation technique that involves tensing and relaxing muscle groups to reduce body tension.
Risk of bias (ROB) | An assessment of study quality. We used the following guidance in this report.; (1) For KQ 1 and KQ 2, we used the Cochrane EPOC ROB tool, which is applicable to randomized and nonrandomized studies^28^:; - Randomization and allocation concealment; - Comparability of groups at baseline; - Blinded outcomes assessment; - Completeness of follow-up and differential loss to follow-up; - Whether incomplete data were addressed appropriately; - Protection against contamination; - Selective outcomes reporting; Summary ROB ratings for a study:; - Low ROB—Bias, if present, is unlikely to alter the results seriously; - Unclear ROB—Bias that raises some doubts about the results; - High ROB—Bias that may alter the results seriously; (2) We used the Critical Appraisal Skills Programme (CASP) criteria to evaluate the ROB for qualitative study designs^30^:; - Clear statement of aims; - Appropriate qualitative methodology; - Appropriate research design; - Appropriate recruitment; - Appropriate data collection; - Consideration of ethical issues; - Sufficiently rigorous data analysis; - Clear statement of findings; - Valuable of the research; (3) We used the Mixed Methods Appraisal Tool (MMAT) 5 items specific to descriptive studies to evaluate the ROB for quantitative descriptive designs^31^:; - Relevant sampling strategy; - Representative sample; - Appropriate measures; - Risk of non-response bias; - Appropriate statistical analysis; We also used the MMAT 5 items for mixed methods to evaluate the ROB for mixed-methods studies^31^:; - Adequate rationale for using a mixed-methods design; - Effective integration of the different components; - Adequate interpretation of the integration of qualitative and quantitative comments; - Adequately addressed inconsistencies between quantitative and qualitative results; - Adherence of the different components to the quality criteria of each method; No summary ROB was possible for the CASP or MMAT.
Standardized mean difference (SMD) | The difference in outcomes between the intervention and comparator, divided by the pooled standard deviation.