# APPENDIX E Excluded Studies

Study | Not full publication | Not eligible country | Not population of interest | Not eligible setting | Not eligible intervention | Not eligible design | Not eligible outcome
Aliasgharpour, 2013^1^ | | ✕
Caller, 2016^2^ | ✕
Cervenka, 2012^3^ | | | | | ✕
Chappell, 1999^4^ | | | | | ✕
Clark, 2001^5^ | | | ✕
Cole, 2015^6^ | | | | | ✕
Collard, 2017^7^ | | | | | | ✕
Crooks, 2017^8^ | | | ✕
Davis, 2004^9^ | | | | ✕
De Barros, 2018^10^ | | | ✕
DiIorio, 2011^11^ | ✕
DiIorio, 2009^12^ | | | | | | ✕
DiIorio, 2009^13^ | | | | | | ✕
DiIorio, 1992^14^ | | | | | ✕
Elsas, 2011^15^ | | | | | | ✕
Endermann, 2015^16^ | | | ✕
Engelberts, 2002^17^ | | | | | ✕
Groenewegen, 2014^18^ | | | | ✕
Helde, 2003^19^ | | | | | ✕
Helde, 2005^20^ | | | | | ✕
Helmstaedter, 2008^21^ | | | | | ✕
Hixson, 2015^22^ | | | | | | ✕
Hixson, 2015^23^ | | | | ✕
Kobau, 2003^24^ | | | | ✕
Kotchoubey, 2001^25^ | | | | | | ✕
Krakow, 1999^26^ | | | | ✕
Kralj-Hans, 2014^27^ | | | | | ✕
Kumar, 2018^28^ | | | | | ✕
Lai, 2018^29^ | | ✕
Leenen, 2014^30^ | | | | ✕
Losada-Camacho, 2014^31^ | | ✕
Lua, 2013^32^ | | ✕
Lundgren, 2008^33^ | | ✕
Lundgren, 2006^34^ | | ✕
Martinovic, 2001^35^ | | ✕
McAuley, 2001^36^ | | | | | ✕
Mejdahl, 2017^37^ | | | | | ✕
Minshall, 2008^38^ | | | ✕
Mody, 2016^39^ | | | | | ✕
Myers, 2017^40^ | | | | ✕
Newman, 2016^41^ | | | | | | ✕
Noble, 2014^42^ | | | | | | ✕
Ogata, 2000^43^ | | | | | ✕
Pakpour, 2015^44^ | | ✕
Peterson, 1984^45^ | | | | | ✕
Peterson, 1982^46^ | | | | | ✕
Pfeifer, 2005^47^ | | | | | ✕
Pramuka, 2007^48^ | | | | | | ✕
Privitera, 2014^49^ | | | | | ✕
Radford, 2011^50^ | | | | | ✕
Rajesh, 2006^51^ | | ✕
Ridsdale, 2013^52^ | | | | | | ✕
Ridsdale, 2002^53^ | | | ✕
Ridsdale, 2000^54^ | | | | | ✕
Ridsdale, 1999^55^ | | | | | ✕
Ridsdale, 1996^56^ | | | | ✕
Rockstroh, 1993^57^ | | | | | ✕
Roth, 1994^58^ | | | | | ✕
Sahoo, 2016^59^ | | | | | ✕
Sajatovic, 2017^60^ | | | | | | ✕
Saramma, 2014^61^ | | ✕
Sathyaprabha, 2008^62^ | | ✕
Sawangchareon, 2013^63^ | | ✕
Schougaard, 2017^64^ | | | | | | ✕
Schroder, 2014^65^ | | | | | ✕
Schröder, 2014^66^ | | | | | ✕
Shaw, 2010^67^ | ✕
Shaw, 2007^68^ | | | | | | ✕
Shegog, 2017^69^ | | | | | | ✕
Smith, 2017^70^ | | | | | | ✕
Smithson, 2013^71^ | | | | | ✕
Spector, 1999^72^ | | | | | | ✕
Staniszewska, 2017^73^ | | | | | ✕
Strehl, 2014^74^ | | | | | | ✕
Sung, 2017^75^ | | | ✕
Tang, 2015^76^ | | ✕
Tatum, 2008^77^ | | | | | ✕
Thompson, 2010^78^ | | | ✕
Trostle, 1983^79^ | | | | | ✕
CDC Epilepsy Program^80^ | | | | | ✕
Walker, 2010^81^ | | | ✕
Walker, 2009^82^ | | | | | | ✕
Wood, 2017^83^ | | | | | | ✕
Yardi, 2001^84^ | | | | | | ✕

## References to Appendix E

1 Aliasgharpour M, Dehgahn Nayeri N, Yadegary MA, . Effects of an educational program on self-management in patients with epilepsy. Seizure. 2013;22(1):48–52.23122512
2 Caller T, Ferguson R, Roth R, . Self-management (HOBSCOTCH) improves cognition and quality of life in epilepsy: a randomized controlled trial. Neurology. Vol. 86; 2016.
3 Cervenka MC, Terao NN, Bosarge JL, . E-mail management of the modified Atkins Diet for adults with epilepsy is feasible and effective. Epilepsia. 2012;53(4):728–32.22332768
4 Chappell B, Smithson H. Meeting the educational needs of general practitioners for epilepsy. Seizure. 1999;8(3):157–62.10356373
5 Clark AJ, Espie CA, Paul A. Adults with learning disabilities and epilepsy: knowledge about epilepsy before and after an educational package. Seizure. 2001;10(7):492–9.11749105
6 Cole KA, Gaspar PM. Implementation of an epilepsy self-management protocol. J Neurosci Nurs. 2015;47(1):3–9.25503542
7 Collard SS, Ellis-Hill C. How do you exercise with epilepsy? Insights into the barriers and adaptations to successfully exercise with epilepsy. Epilepsy Behav. 2017;70(Pt A):66–71.28411518
8 Crooks RE, Bell M, Patten SB, . Mind the gap: Exploring information gaps for the development of an online resource hub for epilepsy and depression. Epilepsy Behav. 2017;70(Pt A):18–23.28407525
9 Davis J, Roberts R, Davidson DL, . Implementation strategies for a Scottish national epilepsy guideline in primary care: results of the Tayside Implementation of Guidelines in Epilepsy Randomized (TIGER) trial. Epilepsia. 2004;45(1):28–34.
10 de Barros ACS, Furlan AER, Marques LHN, . Effects of a psychotherapeutic group intervention in patients with refractory mesial temporal lobe epilepsy and comorbid psychogenic nonepileptic seizures: A nonrandomized controlled study. Seizure. 2018;58:22–28.29609146
11 DiIorio C, Bamps Y, Walker E. Results of a randomized controlled trial evaluating webease, an online self-management program. Epilepsy currents. Vol. 11; 2011.
12 DiIorio C, Reisinger EL, Yeager KA, . A telephone-based self-management program for people with epilepsy. Epilepsy Behav. 2009;14(1):232–6.19010447
13 DiIorio C, Escoffery C, McCarty F, . Evaluation of WebEase: an epilepsy self-management Web site. Health Educ Res. 2009;24(2):185–97.18682382
14 DiIorio C, Faherty B, Manteuffel B. Self-efficacy and social support in self-management of epilepsy. West J Nurs Res. 1992;14(3):292–303; discussion 303–7.1615646
15 Elsas SM, Gregory WL, White G, . Aura interruption: the Andrews/Reiter behavioral intervention may reduce seizures and improve quality of life - a pilot trial. Epilepsy Behav. 2011;22(4):765–72.22056814
16 Endermann M. Rehabilitation for young adults with epilepsy and mild intellectual disabilities: results of a prospective study with repeated measurements. Seizure. 2015;26:72–80.25799906
17 Engelberts NH, Klein M, Ader HJ, . The effectiveness of cognitive rehabilitation for attention deficits in focal seizures: a randomized controlled study. Epilepsia. 2002;43(6):587–95.12060017
18 Groenewegen A, Tofighy A, Ryvlin P, . Measures for improving treatment outcomes for patients with epilepsy--results from a large multinational patient-physician survey. Epilepsy Behav. 2014;34:58–67.24704566
19 Helde G, Brodtkorb E, Brathen G, . An easily performed group education programme for patients with uncontrolled epilepsy--a pilot study. Seizure. 2003;12(7):497–501.12967579
20 Helde G, Bovim G, Brathen G, . A structured, nurse-led intervention program improves quality of life in patients with epilepsy: a randomized, controlled trial. Epilepsy Behav. 2005;7(3):451–7.16087407
21 Helmstaedter C, Loer B, Wohlfahrt R, . The effects of cognitive rehabilitation on memory outcome after temporal lobe epilepsy surgery. Epilepsy Behav. 2008;12(3):402–9.18155965
22 Hixson JD, Barnes D, Parko K, . Patients optimizing epilepsy management via an online community: the POEM Study. Neurology. 2015;85(2):129–36.26085605
23 Hixson JD, Van Bebber SL, Bertko KM. Interest in a digital health tool in veterans with epilepsy: results of a phone survey. Mil Med. 2015;180(4):387–90.25826343
24 Kobau R, DiIorio C. Epilepsy self-management: a comparison of self-efficacy and outcome expectancy for medication adherence and lifestyle behaviors among people with epilepsy. Epilepsy Behav. 2003;4(3):217–25.12791322
25 Kotchoubey B, Strehl U, Uhlmann C, . Modification of slow cortical potentials in patients with refractory epilepsy: a controlled outcome study. Epilepsia. 2001;42(3):406–16.11442161
26 Krakow K, Buhler K, Haltenhof H. Coping with refractory epilepsy. Seizure. 1999;8(2):111–5.10222304
27 Kralj-Hans I, Goldstein LH, Noble AJ, . Self-Management education for adults with poorly controlled epILEpsy (SMILE (UK)): a randomised controlled trial protocol. BMC Neurol. 2014;14:69.24694207
28 Kumar N, Colon-Zimmermann K, Fuentes-Casiano E, . Clinical correlates of negative health events in a research sample with epilepsy. Epilepsy Behav. 2018;79:225–229.29279188
29 Lai ST, Lim KS, Tang V, . Positive psychological interventions for people with epilepsy: An assessment on factors related to intervention participation. Epilepsy Behav. 2018;80:90–97.29414564
30 Leenen LA, Wijnen BF, de Kinderen RJ, . (Cost)-effectiveness of a multi-component intervention for adults with epilepsy: study protocol of a Dutch randomized controlled trial (ZMILE study). BMC Neurol. 2014;14:255.25540089
31 Losada-Camacho M, Guerrero-Pabon MF, Garcia-Delgado P, . Impact of a pharmaceutical care programme on health-related quality of life among women with epilepsy: a randomised controlled trial (IPHIWWE study). Health Qual Life Outcomes. 2014;12:162.25358723
32 Lua PL, Neni WS. A randomised controlled trial of an SMS-based mobile epilepsy education system. J Telemed Telecare. 2013;19(1):23–8.23390210
33 Lundgren T, Dahl J, Yardi N, . Acceptance and Commitment Therapy and yoga for drug-refractory epilepsy: a randomized controlled trial. Epilepsy Behav. 2008;13(1):102–8.18343200
34 Lundgren T, Dahl J, Melin L, . Evaluation of acceptance and commitment therapy for drug refractory epilepsy: a randomized controlled trial in South Africa--a pilot study. Epilepsia. 2006;47(12):2173–9.17201719
35 Martinovic Z. Adjunctive behavioural treatment in adolescents and young adults with juvenile myoclonic epilepsy. Seizure. 2001;10(1):42–7.11181097
36 McAuley JW, Long L, Heise J, . A Prospective Evaluation of the Effects of a 12-Week Outpatient Exercise Program on Clinical and Behavioral Outcomes in Patients with Epilepsy. Epilepsy Behav. 2001;2(6):592–600.12609395
37 Mejdahl CT, Schougaard LMV, Hjollund NH, . PRO-based follow-up as a means of self-management support - an interpretive description of the patient perspective. J Patient Rep Outcomes. 2017;2:38.30238083
38 Minshall I, Smith D. The impact of a citywide audit with educational intervention on the care of patients with epilepsy. Seizure. 2008;17(3):261–8.17913517
39 Mody SK, Haunschild C, Farala JP, . An educational intervention on drug interactions and contraceptive options for epilepsy patients: a pilot randomized controlled trial. Contraception. 2016;93(1):77–80.26197260
40 Myers L, Lancman M, Laban-Grant O, . Socialization characteristics in persons with epilepsy. Epilepsy Behav. 2017;72:99–107.28575775
41 Newman C, Shankar R, Hanna J, . Developing an Evidence-Based Epilepsy Risk Assessment eHealth Solution: From Concept to Market. JMIR Res Protoc. 2016;5(2):e82.27269382
42 Noble AJ, McCrone P, Seed PT, . Clinical- and cost-effectiveness of a nurse led self-management intervention to reduce emergency visits by people with epilepsy. PLoS One. 2014;9(6):e90789.24603669
43 Ogata A, Amano K. A psychosocial approach to epileptic patients. Epilepsia. 2000;41: Suppl 9:36–8.11156509
44 Pakpour AH, Gholami M, Esmaeili R, . A randomized controlled multimodal behavioral intervention trial for improving antiepileptic drug adherence. Epilepsy Behav. 2015;52(Pt A):133–42.26414343
45 Peterson GM, McLean S, Millingen KS. A randomised trial of strategies to improve patient compliance with anticonvulsant therapy. Epilepsia. 1984;25(4):412–7.6430689
46 Peterson GM, McLean S, Millingen KS. Determinants of patient compliance with anticonvulsant therapy. Epilepsia. 1982;23(6):607–13.7173128
47 Pfeifer HH, Thiele EA. Low-glycemic-index treatment: a liberalized ketogenic diet for treatment of intractable epilepsy. Neurology. 2005;65(11):1810–2.16344529
48 Pramuka M, Hendrickson R, Zinski A, . A psychosocial self-management program for epilepsy: a randomized pilot study in adults. Epilepsy Behav. 2007;11(4):533–45.17904909
49 Privitera M, Walters M, Lee I, . Characteristics of people with self-reported stress-precipitated seizures. Epilepsy Behav. 2014;41:74–7.25305436
50 Radford K, Lah S, Thayer Z, . Effective group-based memory training for patients with epilepsy. Epilepsy Behav. 2011;22(2):272–8.21803657
51 Rajesh B, Jayachandran D, Mohandas G, . A pilot study of a yoga meditation protocol for patients with medically refractory epilepsy. J Altern Complement Med. 2006;12(4):367–71.16722786
52 Ridsdale L, McCrone P, Morgan M, . Health Services and Delivery Research. Can an epilepsy nurse specialist-led self-management intervention reduce attendance at emergency departments and promote well-being for people with severe epilepsy? A nonrandomised trial with a nested qualitative phase. Southampton (UK): NIHR Journals Library.
53 Ridsdale L, Kwan I, Morgan M. How can a nurse intervention help people with newly diagnosed epilepsy? A qualitative study (of patients’ views). Seizure. 2002;11(1):1–5.11888253
54 Ridsdale L, Kwan I, Cryer C. Newly diagnosed epilepsy: can nurse specialists help? A randomized controlled trial. Epilepsy Care Evaluation Group. Epilepsia. 2000;41(8):1014–9.10961629
55 Ridsdale L, Kwan I, Cryer C. The effect of a special nurse on patients’ knowledge of epilepsy and their emotional state. Epilepsy Evaluation Care Group. Br J Gen Pract. 1999;49(441):285–9.10736906
56 Ridsdale L, Robins D, Fitzgerald A, . Epilepsy monitoring and advice recorded: general practitioners’ views, current practice and patients’ preferences. Br J Gen Pract. 1996;46(402):11–4.8745845
57 Rockstroh B, Elbert T, Birbaumer N, . Cortical self-regulation in patients with epilepsies. Epilepsy Res. 1993;14(1):63–72.8449180
58 Roth DL, Goode KT, Williams VL, . Physical exercise, stressful life experience, and depression in adults with epilepsy. Epilepsia. 1994;35(6):1248–55.7988518
59 Sahoo SS, Ramesh P, Welter E, . Insight: An ontology-based integrated database and analysis platform for epilepsy self-management research. Int J Med Inform. 2016;94:21–30.27573308
60 Sajatovic M, Jobst BC, Shegog R, . The Managing Epilepsy Well Network:: Advancing Epilepsy Self-Management. Am J Prev Med. 2017;52(3s3):S241–s245.28215372
61 Saramma PP, Sarma PS, Thomas SV. Effect of a self-instructional module on the child rearing knowledge and practice of women with epilepsy. Seizure. 2014;23(6):424–8.24647345
62 Sathyaprabha TN, Satishchandra P, Pradhan C, . Modulation of cardiac autonomic balance with adjuvant yoga therapy in patients with refractory epilepsy. Epilepsy Behav. 2008;12(2):245–52.18024208
63 Sawangchareon K, Pranboon S, Tiamkao S, . Moving the self-esteem of people with epilepsy by supportive group: a clinical trial. J Caring Sci. 2013;2(4):329–35.25276742
64 Schougaard LM, Mejdahl CT, Petersen KH, . Effect of patient-initiated versus fixed-interval telePRO-based outpatient follow-up: study protocol for a pragmatic randomised controlled study. BMC Health Serv Res. 2017;17(1):83.28122609
65 Schroder J, Bruckner K, Fischer A, . Efficacy of a psychological online intervention for depression in people with epilepsy: a randomized controlled trial. Epilepsia. 2014;55(12):2069–76.25410633
66 Schröder J, Brückner K, Fischer A, . Efficacy of a psychological online intervention for depression in people with epilepsy: a randomized controlled trial. Epilepsia. Vol. 55; 2014:2069–2076.25410633
67 Shaw EJ, Stokes T, Camosso-Stefinovic J, . WITHDRAWN: Self-management education for adults with epilepsy. Cochrane Database Syst Rev. 2010(10):Cd004723.
68 Shaw EJ, Stokes T, Camosso-Stefinovic J, . Self-management education for adults with epilepsy. Cochrane Database Syst Rev. 2007(2):Cd004723.
69 Shegog R, Begley CE. Clinic-Based Mobile Health Decision Support to Enhance Adult Epilepsy Self-Management: An Intervention Mapping Approach. Front Public Health. 2017;5:256.29043247
70 Smith A, McKinlay A, Wojewodka G, . A systematic review and narrative synthesis of group self-management interventions for adults with epilepsy. BMC Neurol. 2017;17(1):114.28623909
71 Smithson WH, Hukins D, Buelow JM, . Adherence to medicines and self-management of epilepsy: a community-based study. Epilepsy Behav. 2013;26(1):109–13.23246201
72 Spector S, Tranah A, Cull C, . Reduction in seizure frequency following a short-term group intervention for adults with epilepsy. Seizure. 1999;8(5):297–303.10486295
73 Staniszewska A, Smolenska E, Religioni U. Health Behaviors Related to the Use of Drugs among Patients with Epilepsy. Am J Health Behav. 2017;41(4):511–517.28601110
74 Strehl U, Birkle SM, Worz S, . Sustained reduction of seizures in patients with intractable epilepsy after self-regulation training of slow cortical potentials - 10 years after. Front Hum Neurosci. 2014;8:604.25152725
75 Sung C, Lin CC, Connor A, . Disclose or not? Effect of impression management tactics on hireability of persons with epilepsy. Epilepsia. 2017;58(1):128–136.27869304
76 Tang V, Poon WS, Kwan P. Mindfulness-based therapy for drug-resistant epilepsy: An assessor-blinded randomized trial. Neurology. 2015;85(13):1100–7.26333801
77 Tatum WOt, Al-Saadi S, Orth TL. Outpatient case management in low-income epilepsy patients. Epilepsy Res. 2008;82(2–3):156–61.18801643
78 Thompson NJ, Walker ER, Obolensky N, . Distance delivery of mindfulness-based cognitive therapy for depression: project UPLIFT. Epilepsy Behav. 2010;19(3):247–54.20851055
79 Trostle JA, Hauser WA, Susser IS. The logic of noncompliance: management of epilepsy from the patient’s point of view. Cult Med Psychiatry. 1983;7(1):35–56.6851618
80 U.S. Centers For Disease Control and Prevention Epilepsy Program. Internet use and looking up information online in adults with epilepsy varies by epilepsy status--2013 National Health Interview Survey. Epilepsy Behav. 2016;54:47–9.26655448
81 Walker ER, Obolensky N, Dini S, . Formative and process evaluations of a cognitive-behavioral therapy and mindfulness intervention for people with epilepsy and depression. Epilepsy Behav. 2010;19(3):239–46.20833592
82 Walker ER, Wexler B, DiIorio C, . Content and characteristics of goals created during a self-management intervention for people with epilepsy. J Neurosci Nurs. 2009;41(6):312–21.19998682
83 Wood K, Lawrence M, Jani B, . Mindfulness-based interventions in epilepsy: a systematic review. BMC Neurol. 2017;17(1):52.28320349
84 Yardi N. Yoga for control of epilepsy. Seizure. 2001;10(1):7–12.11181093