# APPENDIX D Study Characteristics Table

For full study citations in this appendix, please refer to the report’s main reference list.