# APPENDIX C Intervention Characteristics Tables

For full study citations in this appendix, please refer to the report’s main reference list.

Randomized Trials

Nonrandomized Trials