# APPENDIX B Peer Review Comments/Author Responses

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 2 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 6 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 7 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 2 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | Yes - Would consider an addendum to include the Sajatovic et al study in Epilepsia Sept 2018, 1684–95. This study appears to have a positive outcome and may offset some to the disappointment of the other negative or inconclusive studies reviewed. | Thank you. We identified this study when we updated our search and it is included in the final report.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | Yes - Sajatovic M et al. A 6-month prospective randomized controlled trial of remotely delivered group format epilepsy self management versus waitlist control for high risk people with epilepsy. Epilepsia. 2018;59 (9):1684–1695) | Thank you. We identified this study when we updated our search and it is included in the final report.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | There are a number of published studies that would make the case for why this is important based on data for Veterans. | We cite Veteran-specific data obtained from the Epilepsy Centers of Excellence.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Recommend clearly defining “self-efficacy” and how this differs from self-management.; On page 3 (and elsewhere) it is stated that 6 educational interventions and 8 psychosocial therapy interventions were included for review in KQ1; however, the Table lists these numbers as 6 and 12 respectively. Please clarify the reason for this difference. | Self-management is carefully defined in the report. We have added a definition for self-efficacy.; This apparent discrepancy relates to the number of studies using the interventions versus the number of intervention arms using the interventions. We have carefully edited to specify studies or intervention arms.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Document is quite thorough, well-written and clear. Though it does not directly address patient centered care or Whole Health, findings regarding the importance of personalization for implementation are relevant.; Pg. 50, lines 9–11; Suggested rewording: Self-management of chronic illness that is aligned with an individual’s values and preferences is considered an important component in delivering patient-centered care in VHA, and is a pillar of VHA’s Patient Aligned Care Teams (PACT).; I am unfamiliar with the reference cited (#75) and am not sure that it is reflective of current perspectives re. Whole Health and PCC in VHA. The Office of Patient Centered Care and Cultural Transformation website is: https://vaww.va.gov/patientcenteredcare/ | Thank you. The suggested edit has been made.; We think the reference is relevant. We have added a link to the Office of Patient Centered Care and Cultural Transformation.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Reference 2 is not sited properly (ref 2 on page 9 does not seem to match ref 2 on page 48).; Could not find a definition regarding how a setting was deemed eligible. | Thank you for detecting this citation error. The citation has been updated (Rehman et al., 2015).; Setting is described in Table 1 (Eligibility Criteria). “Setting” is this instance refers to eligible modes of delivery, rather than a physical location.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | It is well written and valuable to providers in VAH. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | I found following descriptions that may be revised if the most recent publication (see below) will be included. | Thank you. Except as noted, these statements were revised after the addition of the Sajatovic study.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Page 8 (p 2) Data Sources and Searches; We searched MEDLINE (via PubMed), PsycINFO, and CINAHL from inception through April 13, 2018. We also examined the bibliographies of recent reviews for additional relevant studies. | This statement is accurate.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Page 12 (p 6) “No studies directly addressed facilitators and barriers to implementing and adopting self-management interventions for patients with epilepsy in the VHA or other large health systems. No studies directly enrolled Veterans with epilepsy.”; Page 12 (p6) “We found limited evidence for benefit on selected primary or secondary outcomes.; Educational self-management interventions may improve the use of selfmanagement practices.; Sparse evidence suggested possible benefit of psychosocial therapy interventions on self efficacy.; Self-management interventions did not improve other outcomes but the certainty of evidence for these finding was often low.” | These statements about educational interventions were updated.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Page 13 (p7) “None of the included studies were conducted in VHA or specifically with Veterans.”; Page 13 (p7) Conclusions “These self-management interventions showed clinically important benefit for only a limited number of outcomes, but the confidence in these findings was mostly low.” | This statement remains accurate.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | There is a recent article published in Epilepsia September issue of 2018 (Sajatovic M, Colon-Zimmermann K, Kahriman M, Fuentes-Casiano E, Liu H, Tatsuoka C, Cassidy KA, Lhatoo S, Einstadter D, Chen P. A 6-month prospective randomized controlled trial of remotely delivered group format epilepsy self-management versus waitlist control for high-risk people with epilepsy. Epilepsia. 2018;59 (9):1684–1695); This study, if included in this review, will enhance the quality of current review and alter narratives described above in executive summary and through the rest of manuscript of review.; This study was conducted at the Cleveland VA Medical Center, and University Hospitals of Cleveland Neurological Institute, with subjects including veterans. I would recommend to include this study in this review. It is a randomized controlled trial using remotely delivered group format epilepsy self management (n=60) versus waitlist control (n=6) for high risk individuals with epilepsy. This study will help in addressing all 3 questions this review intended to answer, and will enhance the quality of this review.; Summary of this study is as below.; Objective: Despite advances in care, many people with epilepsy have negative health events (NHEs) such as accidents, emergency department visits, and poor quality of life. Self-management for people with epilepsy and a history of negative health events”(SMART) is a novel group format epilepsy self-management intervention. A community participatory approach informed the refinement of SMART, which was then tested in a 6-month randomized controlled trial of SMART (n = 60) versus waitlist control (WL, n = 60).; Methods: Participants were adults aged ≥18 years with epilepsy and an NHE within the past 6 months (seizure, accident, self-harm attempt, emergency department visit, or hospitalization). Assessments were conducted at screening, baseline, 10 weeks, and 24 weeks (6 months). Primary outcome was 6-month change in total NHE count. Additional outcomes included depression on the nine-item Patient Health Questionnaire and Montgomery-Asberg Depression Rating Scale, quality of life on the 10-item Quality of Life in Epilepsy, functioning on the 36-item Short-Form Health Survey, and seizure severity on the Liverpool Seizure Severity Scale.; Results: Mean age was 41.3 years (SD = 11.82), 69.9% were African American, 74.2% were unemployed, and 87.4% had an annual income < US$25 000; 57.5% had a seizure within 30 days of enrollment. Most NHEs were seizures. Six-month study attrition was 14.2% overall and similar between arms. Individuals randomized to SMART had greater reduction in total median NHEs from baseline to 6 months compared to WL (P = 0.04). SMART was also associated with improved nine-item Patient Health Questionnaire (P = 0.032), Montgomery-Asberg Depression Rating Scale (P = 0.002), 10 item Quality of Life in Epilepsy (P < 0.001), and 36-item Short-Form Health Survey (P = 0.015 physical health, P = 0.003 mental health) versus WL. There was no difference in seizure severity.; Significance: SMART is associated with reduced health complications and improved mood, quality of life, and health functioning in high-risk people with epilepsy. Additional efforts are needed to investigate potential for scale up. | This study is included in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Curriculum of “Self-management for people with epilepsy and a history of negative health events” (SMART)
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Session 1 Orientation and introductions; Emphasize ground rules; Establishment of a therapeutic relationship; Facts and myths about epilepsy and general epilepsy management principles; Session 2 Relationship of epilepsy and stress; Stigma and “double stigma”; Strategies to cope with stigma; Introduction to personal goalsetting; Session 3 Treatments for epilepsy; Complications of epilepsy; Minimizing epilepsy complications; The importance of daily routine and good sleep habits; Session 4 Problem-solving skills and the IDEA approach (Identify the problem, Define possible solutions, Evaluate the solutions, Act on the best solution); Talking with your health care providers; Role play of communication with care providers; Session 5 Nutrition for best physical and emotional health; Substance abuse and its effects on epilepsy; Specific stressmanagement approaches; Session 6 Effects of exercise and being outdoors on physical and emotional health; Medication routines; Prioritizing medication side effects and discussing it with your clinician; Session 7 Social supports and using your available supports; Advocacy groups for epilepsy; A personal care plan to take care of the mind and the body; Session 8 Normalizing your life in spite of having a chronic but unpredictable condition; Self- management as a life-style; Acknowledgement of group progress; Setting the stage for Ongoing Illness Management and Recovery (Step 2)
| 7 | The references in the body of the document seemed to be the wrong references. | Thank you, the references have been updated.