# APPENDIX A Search Strategies

PubMed: April 13, 2018 and October 31, 2018

Set | Terms | Results
#1 | “Epilepsy”[Mesh] OR epilepsy[tiab] OR epilepsies[tiab] OR epileptic[tiab] OR epileptics[tiab] OR epilepsia[tiab] | 139,312
#2 | “Self-Management”[Mesh] OR “Self Care”[Mesh] OR “Self-Control”[Mesh] OR self[tiab] OR selfcare[tiab] OR selfmanagement[tiab] OR selftreatment[tiab] OR selfcontrol[tiab] OR selfhelp[tiab] | 646,690
#3 | “Patient Compliance”[Mesh] OR “Medication Adherence”[tiab] OR “Medication Compliance”[tiab] OR “Medication nonadherence”[tiab] OR “Medication non adherence”[tiab] OR “Medication Noncompliance”[tiab] OR “Medication non compliance”[tiab] OR “Medication Persistence”[tiab] OR “Health Knowledge, Attitudes, Practice”[Mesh] | 162,567
#4 | “Behavior Therapy”[Mesh] OR behavior therap*[tiab] OR behaviour therap*[tiab] OR behavioral therap*[tiab] OR behavioural therap*[tiab] OR “anger management”[tiab] OR biofeedback[tiab] OR “bio-feedback”[tiab] OR myobiofeedback[tiab] OR myofeedback[tiab] OR “physiological feedback”[tiab] OR “neuro feedback”[tiab] OR neurofeedback[tiab] OR cognitive therap*[tiab] OR cognition therap*[tiab] OR acceptance therap*[tiab] OR commitment therap*[tiab] OR mindfulness[tiab] OR “MBSR”[tiab] OR “psychologic desensitization”[tiab] OR “psychological desensitization”[tiab] OR “Eye Movement Desensitization and Processing”[tiab] OR EMDR[tiab] OR implosive therap*[tiab] OR exposure therap*[tiab] OR relaxation therap*[tiab] OR “relaxation techniques”[tiab] OR “relaxation technique”[tiab] OR “meditation”[tiab] OR meditate[tiab] OR meditates[tiab] OR “Mind-Body Therapies”[Mesh:NoExp] OR “mind body therapy”[tiab] OR “mind body therapies”[tiab] OR “mind body medicine”[tiab] OR “Breathing Exercises”[Mesh] OR “breathing exercise”[tiab] OR “breathing exercises”[tiab] OR “respiratory muscle training”[tiab] OR “paced respiration”[tiab] OR “Imagery (Psychotherapy)”[Mesh] OR “guided imagery”[tiab] OR “Alexander Technique”[tiab] OR problem-solving therap*[tiab] OR psychodynamic therap*[tiab] OR psychotherap*[tiab] OR “stress reduced”[tiab] OR “stress reducer”[tiab] OR” stress reducers”[tiab] OR “stress reducing”[tiab] OR “stress reduction”[tiab] OR “stress reductions”[tiab] OR “stress reductive”[tiab] | 125,605
#5 | #1 AND (#2 OR #3 OR #4) AND English[lang] | 3,887
#6 | #5 NOT (animals[mh] NOT humans[mh]) NOT ((“Adolescent”[Mesh] OR “Child”[Mesh] OR “Infant”[Mesh]) NOT “Adult”[Mesh]) | 3,080
#7 | #6 AND ((“randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR drug therapy[sh] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR (controlled[tiab] AND (trial[tiab] OR study[tiab])) OR “prepost”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR pre-test[tiab] OR (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab])) NOT (Editorial[ptyp] OR Letter[ptyp] OR Comment[ptyp])) | 1,695
#8 | #6 AND ((“Delivery of Health Care”[Mesh] OR “healthcare delivery”[tiab] OR “health care delivery”[tiab] OR “healthcare system”[tiab] OR “healthcare systems”[tiab] OR “health care system”[tiab] OR “health care systems”[tiab] OR “Health Facilities”[Mesh] OR outpatient[tiab] OR outpatients[tiab] OR clinic[tiab] OR clinics[tiab] OR “primary care”[tiab] OR program[tiab] OR programs[tiab] OR programme[tiab] OR programmes[tiab] OR protocol[tiab] OR protocols[tiab] OR policy[tiab] OR policies[tiab] OR guideline[tiab] OR guidelines[tiab] OR “standards”[Subheading] OR standard[tiab] OR standards[tiab] OR initiative[tiab] OR initiatives[tiab] OR strategy[tiab] OR strategies[tiab] OR “Evidence-Based Practice”[Mesh]) AND (“Program Evaluation”[Mesh] OR “Outcome and Process Assessment (Health Care)”[Mesh] OR “Diffusion of Innovation”[Mesh] OR implement[tiab] OR implements[tiab] OR implementation[tiab] OR implemented[tiab] OR implementing[tiab] OR preimplementation[tiab] OR postimplementation[tiab] OR uptake[tiab] OR adopt*[tiab] OR adapt*[tiab] OR facilitator*[tiab] OR feasible[tiab] OR feasibility[tiab] OR effective[tiab] OR effectiveness[tiab] OR barrier[tiab] OR barriers[tiab] OR benefit[tiab] OR benefits[tiab])) | 568
#9 | #7 OR #8 | 1,860

Cochrane Central: April 13, 2018

Set | Terms | Results
#1 | [mh Epilepsy] OR (epilepsy or epilepsies or epileptic or epileptics or epilepsia):ti,ab,kw | 5,832
#2 | [mh “Self-Management”] OR [mh “Self Care”] OR [mh “Self-Control”] OR (self OR selfcare OR selfmanagement OR selftreatment OR selfcontrol OR selfhelp):ti,ab,kw | 62,762
#3 | [mh “Patient Compliance”] OR [mh “Health Knowledge, Attitudes, Practice”] OR (“Medication Adherence” OR “Medication Compliance” OR “Medication nonadherence” OR “Medication non adherence” OR “Medication Noncompliance” OR “Medication non compliance” OR “Medication Persistence”):ti,ab,kw | 18,270
#4 | [mh “Behavior Therapy”] OR [mh^ “Mind-Body Therapies”] OR [mh “Breathing Exercises”] OR [mh “Imagery (Psychotherapy)”] OR ((behavior near/2 therap*) or (behaviour near/2 therap*) or (behavioral near/2 therap*) or (behavioural near/2 therap*) OR “anger management” OR biofeedback OR “bio-feedback” OR myobiofeedback OR myofeedback OR “physiological feedback” OR “neuro feedback” OR neurofeedback OR (cognitive NEAR/2 therap*) OR (cognition NEAR/2 therap*) OR (acceptance NEAR/2 therap*) OR (commitment NEAR/2 therap*) OR mindfulness OR MBSR OR “psychologic desensitization” OR “psychological desensitization” OR “Eye Movement Desensitization and Processing” OR EMDR OR (implosive NEAR/2 therap*) OR (exposure NEAR/2 therap*) OR (relaxation NEAR/2 therap*) OR “relaxation techniques” OR “relaxation technique” OR meditation OR meditate OR meditates OR “mind body therapy” OR “mind body therapies” OR “mind body medicine” OR “breathing exercise” OR “breathing exercises” OR “respiratory muscle training” OR “paced respiration” OR “guided imagery” OR “Alexander Technique” OR (“problem-solving” NEAR/2 therap*) OR (psychodynamic NEAR/2 therap*) OR psychotherap* OR “stress reduced” OR “stress reducer” OR “stress reducers” OR “stress reducing” OR “stress reduction” OR “stress reductions” OR “stress reductive”):ti,ab,kw | 37,550
#5 | #1 AND (#2 OR #3 OR #4) AND English[lang] | 432
#6 | #5 NOT (([mh Adolescent] OR [mh Child] OR [mh Infant]) NOT [mh Adult]) | 326

PsycINFO: April 13, 2018

Set | Terms | Results
S1 | DE “Epilepsy” OR DE “Epileptic Seizures” OR TI (epilepsy OR epilepsies OR epileptic OR epileptics OR epilepsia) OR AB (epilepsy OR epilepsies OR epileptic OR epileptics OR epilepsia) | 38,409
S2 | DE “Self-Management” OR DE “Self-Monitoring” OR DE “Self-Control” OR TI (self OR selfcare OR selfmanagement OR selftreatment OR selfcontrol OR selfhelp) OR AB (“self-care*” OR “self-manage*” OR “self-treat*” OR “self-control” OR “self-help” OR “self care” OR “self management” OR “self treatment” OR “self control” OR “self help” OR selfcare OR selfmanagement OR selftreatment OR selfcontrol OR selfhelp) | 160,644
S3 | DE “Compliance” OR DE “Treatment Compliance” OR DE “Health Attitudes” OR TI (“Medication Adherence” OR “Medication Compliance” OR “Medication nonadherence” OR “Medication non adherence” OR “Medication Noncompliance” OR “Medication non compliance” OR “Medication Persistence”) OR AB (“Medication Adherence” OR “Medication Compliance” OR “Medication nonadherence” OR “Medication non adherence” OR “Medication Noncompliance” OR “Medication non compliance” OR “Medication Persistence”) | 29,260
S4 | DE “Behavior Therapy” OR DE “Guided Imagery” OR DE “Alternative Medicine” OR DE “Stress and Coping Measures” OR DE “Stress Management” OR DE “Emotional Control” OR DE “Anger Control” OR DE “Relaxation Therapy” OR DE “Progressive Relaxation Therapy” OR DE “Mindfulness” OR AB (“behavior therap*” OR “behaviour therap*” OR “behavioral therap*” OR “behavioural therap*” OR “anger management” OR biofeedback OR “bio-feedback” OR myobiofeedback OR myofeedback OR “physiological feedback” OR “neuro feedback” OR neurofeedback OR “cognitive therap*” OR “cognition therap*” OR “acceptance therap*” OR “commitment therap*” OR mindfulness OR “MBSR” OR “psychologic desensitization” OR “psychological desensitization” OR “Eye Movement Desensitization and Processing” OR EMDR OR “implosive therap*” OR “exposure therap*” OR “relaxation therap*” OR “relaxation techniques” OR “relaxation technique” OR meditation OR meditate OR meditates OR “mind body therapy” OR “mind body therapies” OR “mind body medicine” OR “breathing exercise” OR “breathing exercises” OR “respiratory muscle training” OR “paced respiration” OR “guided imagery” OR “Alexander Technique” OR “problemsolving therap*” OR “psychodynamic therap*” OR psychotherap* OR “stress reduced” OR “stress reducer” OR “stress reducers” OR “stress reducing” OR “stress reduction” OR “stress reductions” OR “stress reductive”) OR TI (“behavior therap*” OR “behaviour therap*” OR “behavioral therap*” OR “behavioural therap*” OR “anger management” OR biofeedback OR “bio-feedback” OR myobiofeedback OR myofeedback OR “physiological feedback” OR “neuro feedback” OR neurofeedback OR “cognitive therap*” OR “cognition therap*” OR “acceptance therap*” OR “commitment therap*” OR mindfulness OR MBSR OR “psychologic desensitization” OR “psychological desensitization” OR “Eye Movement Desensitization and Processing” OR EMDR OR “implosive therap*” OR “exposure therap*” OR “relaxation therap*” OR “relaxation techniques” OR “relaxation technique” OR meditation OR meditate OR meditates OR “mind body therapy” OR “mind body therapies” OR “mind body medicine” OR “breathing exercise” OR “breathing exercises” OR “respiratory muscle training” OR “paced respiration” OR “guided imagery” OR “Alexander Technique” OR “problem-solving therap*” OR “psychodynamic therap*” OR psychotherap* OR “stress reduced” OR “stress reducer” OR “stress reducers” OR “stress reducing” OR “stress reduction” OR “stress reductions” OR “stress reductive”) | 183,898
S5 | S1 AND (S2 OR S3 OR S4) Limiters - Publication Type: All Journals; Language: English; Age Groups: Adulthood (18 yrs & older); Population Group: Human; Document Type: Journal Article; Exclude Dissertations | 583

CINAHL: April 13, 2018

Set | Terms | Results
S1 | (MH “Epilepsy+”) OR TI (epilepsy OR epilepsies OR epileptic OR epileptics OR epilepsia) OR AB (epilepsy OR epilepsies OR epileptic OR epileptics OR epilepsia) | 18,173
S2 | (MH “Self Care+”) OR TI (self OR selfcare OR selfmanagement OR selftreatment OR selfcontrol OR selfhelp) OR AB (“self-care*” OR “self-manage*” OR “self-treat*” OR “self-control” OR “self-help” OR “self care” OR “self management” OR “self treatment” OR “self control” OR “self help” OR selfcare OR selfmanagement OR selftreatment OR selfcontrol OR selfhelp) | 97,606
S3 | (MH “Patient Compliance+”) OR (MH “Attitude to Health+”) OR TI (“Medication Adherence” OR “Medication Compliance” OR “Medication nonadherence” OR “Medication non adherence” OR “Medication Noncompliance” OR “Medication non compliance” OR “Medication Persistence”) OR AB (“Medication Adherence” OR “Medication Compliance” OR “Medication nonadherence” OR “Medication non adherence” OR “Medication Noncompliance” OR “Medication non compliance” OR “Medication Persistence”) | 129,591
S4 | (MH “Behavior Modification+”) OR (MH “Guided Imagery”) OR (MH “Control (Psychology)+”) OR (MH “Biofeedback”) OR AB (“behavior therap*” OR “behaviour therap*” OR “behavioral therap*” OR “behavioural therap*” OR “anger management” OR biofeedback OR “bio-feedback” OR myobiofeedback OR myofeedback OR “physiological feedback” OR “neuro feedback” OR neurofeedback OR “cognitive therap*” OR “cognition therap*” OR “acceptance therap*” OR “commitment therap*” OR mindfulness OR “MBSR” OR “psychologic desensitization” OR “psychological desensitization” OR “Eye Movement Desensitization and Processing” OR EMDR OR “implosive therap*” OR “exposure therap*” OR “relaxation therap*” OR “relaxation techniques” OR “relaxation technique” OR meditation OR meditate OR meditates OR “mind body therapy” OR “mind body therapies” OR “mind body medicine” OR “breathing exercise” OR “breathing exercises” OR “respiratory muscle training” OR “paced respiration” OR “guided imagery” OR “Alexander Technique” OR “problemsolving therap*” OR “psychodynamic therap*” OR psychotherap* OR “stress reduced” OR “stress reducer” OR “stress reducers” OR “stress reducing” OR “stress reduction” OR “stress reductions” OR “stress reductive”) OR TI (“behavior therap*” OR “behaviour therap*” OR “behavioral therap*” OR “behavioural therap*” OR “anger management” OR biofeedback OR “bio-feedback” OR myobiofeedback OR myofeedback OR “physiological feedback” OR “neuro feedback” OR neurofeedback OR “cognitive therap*” OR “cognition therap*” OR “acceptance therap*” OR “commitment therap*” OR mindfulness OR MBSR OR “psychologic desensitization” OR “psychological desensitization” OR “Eye Movement Desensitization and Processing” OR EMDR OR “implosive therap*” OR “exposure therap*” OR “relaxation therap*” OR “relaxation techniques” OR “relaxation technique” OR meditation OR meditate OR meditates OR “mind body therapy” OR “mind body therapies” OR “mind body medicine” OR “breathing exercise” OR “breathing exercises” OR “respiratory muscle training” OR “paced respiration” OR “guided imagery” OR “Alexander Technique” OR “problem-solving therap*” OR “psychodynamic therap*” OR psychotherap* OR “stress reduced” OR “stress reducer” OR “stress reducers” OR “stress reducing” OR “stress reduction” OR “stress reductions” OR “stress reductive”) | 71,641
S5 | S1 AND (S2 OR S3 OR S4) Limiters - English Language; Age Groups: All Adult; Publication Type: Journal Article | 238

Searches retrieved 2,996 records before duplicates were removed.