# Acknowledgments

This topic was developed in response to a nomination by Glenn Graham, Deputy National Director of Neurology, and John Hixson, Associate Professor of Neurology, for the purpose of identifying the current evidence base and its quality to support the use of self-management programs aimed at patients with epilepsy; identifying the program components that contribute most to effectiveness; and identifying potential barriers in the adoption of these programs within the VHA system. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the Technical Expert Panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on the draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Glenn Graham, MD, PhD
  Deputy National Director of Neurology
- John Hixson, MD
  Associate Professor of Neurology
  Epilepsy Center of Excellence (ECoE), San Francisco VA Medical Center
  Neurology Program Office, VHA

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress.

- Jennifer Patterson, PhD
  Senior Whole Health Consultant
  Office of Patient Centered Care & Cultural Transformation
  VA Sierra Nevada Health Care System
  Reno, Nevada
- Paul Rutecki, MD
  Neurology Service Chief
  William S. Middleton Veterans Hospital
  Madison, Wisconsin
  National Director VA Epilepsy Centers of Excellence
  Professor of Neurology and Neurosurgery
  University of Wisconsin-Madison

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or nonfinancial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.