# REFERENCES

1 Fazel S, Geddes JR, Kushel M. The health of homeless people in high-income countries: descriptive epidemiology, health consequences, and clinical and policy recommendations. Lancet. 2014;384(9953):1529–40.25390578
2 Baggett TP, Hwang SW, O’Connell JJ, . Mortality among homeless adults in Boston: shifts in causes of death over a 15-year period. JAMA Intern Med. 2013;173(3):189–95.23318302
3 Kerker BD, Bainbridge J, Kennedy J, . A population-based assessment of the health of homeless families in New York City, 2001-2003. Am J Public Health. 2011;101(3):546–53.21233439
4 National Alliance on Mental Illness. Mental Health by the Numbers. [Website]. Available at: https://nami.org/mhstats. Accessed October 12, 2020.
5 National Coalition for the Homeless. Mental Illness and Homelessness. Available at: www.nationalhomeless.org/factsheets/Mental_Illness.pdf. Accessed March 22, 2021. 2009.
6 Tsai J, Doran KM, Rosenheck RA. When health insurance is not a factor: national comparison of homeless and nonhomeless US veterans who use Veterans Affairs Emergency Departments. Am J Public Health. 2013;103 Suppl 2:S225–31.24148061
7 Department of Housing and Urban Development. The 2015 Annual Homelessness Assessment Report (AHAR) to Congress, 2015. Available at: https://www.hudexchange.info/resource/4832/2015-ahar-part-1-pit-estimates-of-homelessness/. Accessed October 12, 2020.
8 Smith JD, Mittal D, Chekuri L, . A comparison of provider attitudes toward serious mental illness across different health care disciplines. Stigma and Health. 2017;2(4):327–337.
9 Jones AL, Thomas R, Hedayati DO, . Patient predictors and utilization of health services within a medical home for homeless persons. Subst Abuse. 2018;39(3):354–360.
10 Childress S, Reitzel LR, Maria DS, . Mental illness and substance use problems in relation to homelessness onset. Am J Health Behav. 2015;39(4):549–55.26018103
11 Kushel MB, Gupta R, Gee L, . Housing instability and food insecurity as barriers to health care among low-income americans. J Gen Intern Med. 2006;21(1):71–77.16423128
12 Omerov P, Craftman Å G, Mattsson E, . Homeless persons’ experiences of health- and social care: A systematic integrative review. Health Soc Care Community. 2020;28(1):1–11.31524327
13 Gerrity M. Integrating Primary Care into Behavioral Health Settings: What Works for Individuals with Serious Mental Illness (2014). Available at: https://www.milbank.org/publications/integrating-primary-care-into-behavioral-health-settings-what-works-for-individuals-with-serious-mental-illness/. Accessed January 25, 2021.
14 Health Quality Ontario. Interventions to Improve Access to Primary Care for People Who Are Homeless: A Systematic Review. Ont Health Technol Assess Ser. 2016;16(9):1–50.
15 Jego M, Abcaya J, Ștefan DE, . Improving Health Care Management in Primary Care for Homeless People: A Literature Review. Int J Environ Res Public Health. 2018;15(2).
16 O’Toole TP, Buckel L, Bourgault C, . Applying the chronic care model to homeless veterans: effect of a population approach to primary care on utilization and clinical outcomes. Am J Public Health. 2010;100(12):2493–9.20966377
17 Gundlapalli AV, Redd A, Bolton D, . Patient-aligned Care Team Engagement to Connect Veterans Experiencing Homelessness With Appropriate Health Care. Med Care. 2017;55 Suppl 9 Suppl 2:S104–S110.28806373
18 Schick V, Wiginton L, Crouch C, . Integrated Service Delivery and Health-Related Quality of Life of Individuals in Permanent Supportive Housing Who Were Formerly Chronically Homeless. Am J Public Health. 2019;109(2):313–319.30649948
19 Rosenheck RA, Dennis D. Time-limited assertive community treatment for homeless persons with severe mental illness. Arch Gen Psychiatry. 2001;58(11):1073–1080.11695955
20 McHugo GJ, Bebout RR, Harris M, . A randomized controlled trial of integrated versus parallel housing services for homeless adults with severe mental illness. Schizophr Bull. 2004;30(4):969–82.15957201
21 Miake-Lye IM, Hempel S, Shanman R, . What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Syst Rev. 2016;5(1):28.26864942
22 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. PLoS Med. 2009;6(7):e1000097–e1000097.19621072
23 Department of Veterans Affairs. Patient Care Services [website]. Available at: https://www.patientcare.va.gov/primarycare/index.asp#:~:text=Primary%20Care%20(PC)%20gives%20eligible,professionals%20familiar%20with%20their%20needs.&text=VA%20Primary%20Care%20honors%20America’s,of%20their%20health%20care%20team (https://www.patientcare.va.gov/primarycare/index.asp#:%7E:text=Primary%20Care%20(PC)%20gives%20eligible,professionals%20familiar%20with%20their%20needs.&text=VA%20Primary%20Care%20honors%20America’s,of%20their%20health%20care%20team). Accessed November 4, 2020.
24 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors Accessed May 12, 2020.
25 Lewin S, Hendry M, Chandler J, . Assessing the complexity of interventions within systematic reviews: development, content and use of a new tool (iCAT_SR). BMC Med Res Methodol. 2017;17(1):76.28446138
26 Resources for Integrated Care. Behavioral Health Integration Capacity Assessment Tool. Available at: https://www.resourcesforintegratedcare.com/tool/bhica. Accessed January 25, 2021.
27 Health Resources & Services Administration. Integrated Practice Assessment Tool (IPAT). Available at: https://www.hrsa.gov/behavioral-health/integrated-practice-assessment-tool-ipat. Accessed January 25, 2021.
28 Stergiopoulos V, Gozdzik A, Nisenbaum R, . Bridging Hospital and Community Care for Homeless Adults with Mental Health Needs: Outcomes of a Brief Interdisciplinary Intervention. Can J Psychiatry. 2018;63(11):774–784.29716396
29 Corrigan PW, Pickett S, Schmidt A, . Peer navigators to promote engagement of homeless African Americans with serious mental illness in primary care. Psychiatry Res. 2017;255:101–103.28535474
30 Stanhope V, Henwood BF. Activating people to address their health care needs: learning from people with lived experience of chronic illnesses. Community Ment Health J. 2014;50(6):656–63.24337522
31 Kelly EL, Braslow JT, Brekke JS. Using Electronic Health Records to Enhance a Peer Health Navigator Intervention: A Randomized Pilot Test for Individuals with Serious Mental Illness and Housing Instability. Community Ment Health J. 2018;54(8):1172–1179.29725878
32 Baker J, Travers JL, Buschman P, . An Efficient Nurse Practitioner-Led Community-Based Service Model for Delivering Coordinated Care to Persons With Serious Mental Illness at Risk for Homelessness. J Am Psychiatr Nurses Assoc. 2018;24(2):101–108.28402750
33 Corrigan PW, Kraus DJ, Pickett SA, . Using Peer Navigators to Address the Integrated Health Care Needs of Homeless African Americans With Serious Mental Illness. Psychiatr Serv. 2017;68(3):264–270.28093056
34 Stergiopoulos V, Schuler A, Nisenbaum R, . The effectiveness of an integrated collaborative care model vs. a shifted outpatient collaborative care model on community functioning, residential stability, and health service use among homeless adults with mental illness: a quasi-experimental study. BMC Health Serv Res. 2015;15:348.26315398
35 Weinstein LC, Lanoue MD, Plumb JD, . A primary care-public health partnership addressing homelessness, serious mental illness, and health disparities. J Am Board Fam Med. 2013;26(3):279–87.23657696
36 Rivas-Vazquez RA, Sarria M, Rey G, . A relationship-based care model for jail diversion. Psychiatr Serv. 2009;60(6):766–71.19487345
37 McGuire J, Gelberg L, Blue-Howells J, . Access to primary care for homeless veterans with serious mental illness or substance abuse: a follow-up evaluation of co-located primary care and homeless social services. Adm Policy Ment Health. 2009;36(4):255–64.19280333
38 Cheng AL, Kelly PJ. Impact of an integrated service system on client outcomes by gender in a national sample of a mentally ill homeless population. Gend Med. 2008;5(4):395–404.19108812
39 Steadman HJ, Cocozza JJ, Dennis DL, . Successful program maintenance when federal demonstration dollars stop: the ACCESS program for homeless mentally ill persons. Adm Policy Ment Health. 2002;29(6):481–93.12469702
40 Rosenheck RA, Lam J, Morrissey JP, . Service systems integration and outcomes for mentally ill homeless persons in the ACCESS program. Access to Community Care and Effective Services and Supports. Psychiatr Serv. 2002;53(8):958–66.12161669
41 Cocozza JJ, Steadman HJ, Dennis DL, . Successful systems integration strategies: the access program for persons who are homeless and mentally ill. Adm Policy Ment Health. 2000;27(6):395–407.11077703
42 Calloway MO, Morrissey JP. Overcoming service barriers for homeless persons with serious psychiatric disorders. Psychiatr Serv. 1998;49(12):1568–72.9856618
43 Rosenheck R, Lam JA. Homeless mentally ill clients’ and providers’ perceptions of service needs and clients’ use of services. Psychiatr Serv. 1997;48(3):381–6.9057242
44 Morrissey J, Calloway M, Johnsen M, . Service system performance and integration: a baseline profile of the ACCESS demonstration sites. Access to Community Care and Effective Services and Supports. Psychiatr Serv. 1997;48(3):374–80.9057241
45 Rosenheck R, Gallup P, Frisman LK. Health care utilization and costs after entry into an outreach program for homeless mentally ill veterans. Hosp Community Psychiatry. 1993;44(12):1166–71.8132189
46 Weinstein LC, LaNoue M, Collins E, . Health care integration for formerly homeless people with serious mental illness. J Dual Diagn. 2013;9(1):72–77.
47 Patterson M, Somers J, Moniruzzaman A. Sealing the cracks: Preliminary findings from an inter-ministry initiative to address chronic homelessness in British Columbia. J Interprof Care. 2012;26(5):426–428.22734937
48 Solomon P. Services to severely mentally disabled homeless persons and to emergency food and shelter providers. Psychosoc Rehabil J. 1988;12(2):3–13.
49 Stergiopoulos V, O’Campo P, Gozdzik A, . Moving from rhetoric to reality: adapting Housing First for homeless individuals with mental illness from ethno-racial groups. BMC Health Serv Res. 2012;12:345.23031406
50 Padgett D, Henwood BF, Tsemberis SJ. Housing First: Ending homelessness, transforming systems, and changing lives. Oxford University Press, USA, 2016.
51 Kelly E, Duan L, Cohen H, . Integrating behavioral healthcare for individuals with serious mental illness: A randomized controlled trial of a peer health navigator intervention. Schizophr Res. 2017;182:135–141.27793514
52 O’Toole TP, Johnson EE, Borgia ML, . Tailoring Outreach Efforts to Increase Primary Care Use Among Homeless Veterans: Results of a Randomized Controlled Trial. J Gen Intern Med. 2015;30(7):886–98.25673574
53 Bradford DW, Slubicki MN, McDuffie J, . VA Evidence-based Synthesis Program Reports. Effects of Care Models to Improve General Medical Outcomes for Individuals With Serious Mental Illness. Washington (DC): Department of Veterans Affairs (US); 2011.
54 Young AS, Cohen AN, Chang ET, . A clustered controlled trial of the implementation and effectiveness of a medical home to improve health care of people with serious mental illness: study protocol. BMC Health Serv Res. 2018;18(1):428.29880047
55 Resnick SG, Rosenheck R. Dissemination of supported employment in Department of Veterans Affairs. J Rehabil Res Dev. 2007;44(6):867–77.18075943
56 Boland L, Slade A, Yarwood R, . Determinants of Tenancy Sustainment Following Homelessness: A Systematic Review. Am J Public Health. 2018;108(11):e1–e8.
57 Cotterill S, Knowles S, Martindale A-M, . Getting messier with TIDieR: embracing context and complexity in intervention reporting. BMC Med Res Methodol. 2018;18(1):12.29347910
58 Shepherd-Banigan M, Sperber N, McKenna K, . Leveraging institutional support for family caregivers to meet the health and vocational needs of persons with disabilities. Nurs Outlook. 2020;68(2):184–193.31570147
59 Zeiss AM, Karlin BE. Integrating Mental Health and Primary Care Services in the Department of Veterans Affairs Health Care System. J Clin Psychol Med Settings. 2008;15(1):73–78.19104957
60 Morrissey JP, Calloway MO, Thakur N, . Integration of service systems for homeless persons with serious mental illness through the ACCESS program. Access to Community Care and Effective Services and Supports. Psychiatr Serv. 2002;53(8):949–57.12161668
61 Rosenheck R, Lam JA. Client and site characteristics as barriers to service use by homeless persons with serious mental illness. Psychiatr Serv. 1997;48(3):387–90.9057243
62 Stergiopoulos V, Gozdzik A, Nisenbaum R, . Integrating Hospital and Community Care for Homeless People with Unmet Mental Health Needs: Program Rationale, Study Protocol and Sample Description of a Brief Multidisciplinary Case Management Intervention. International Journal of Mental Health and Addiction. 2017;15(2):362–378.