# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by the National Center on Homelessness Among Veterans to inform development of a new program to enhance primary care utilization among Veterans with experiences of homelessness and serious mental illness (SMI). The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the report team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Dina Hooshyar, MD, MPH
  Director, National Center on Homelessness Among Veterans

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Daniel Bradford, MD, MPH
  National Director, Intensive Case Management Services, VA Central Office
  Durham, NC
- Nicholas Bowersox, PhD, ABPP
  Director, VA QUERI Center for Evaluation and Implementation
  Ann Arbor, MI
- Evelyn Chang, MD
  Physician and Health Services Researcher at Department of Veterans Affairs
  West Los Angeles, CA
- Sonya Gabrielian MD, MPH
  Physician and Health Services Researcher at Department of Veterans Affairs
  West Los Angeles, CA
- Andrew Pomerantz, MD
  National Mental Health Director, Integrated Care, VA Central Office
  Washington, DC
- Michal Wilson, MD
  Medical Advisor, Homeless Programs, VA Central Office
  Washington, DC

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.