# SUMMARY AND DISCUSSION

We conducted an evidence map of interventions evaluated to promote primary care engagement of individuals with SMI and experiences of homelessness or who have housing insecurity. Overall, a modest body of literature has been published in this area, largely during the last 30 years. Most of the identified literature comprised program evaluations or observational studies of existing health system- or community-based programs, primarily from outside the VA but all within the United States or Canada. Few programs were solely focused on linking the target population to primary care; rather, connecting patients to longitudinal medical care was most often 1 of multiple intervention goals. Interventions were complex, particularly due to the employment of varied combinations of intervention strategies targeting multiple patient behaviors. Outcome measures were variable across studies with most at the patient level, and few studies measured engagement of primary care.

We identified 15 unique studies evaluating interventions to promote engagement in primary care for adults with experiences of homelessness and SMI). One study, ACCESS, was a multisite comparative program evaluation of a large HHS-funded demonstration project in the United States to improve population health for persons with experiences of homelessness and mental illness. The 14 other studies evaluated community and healthcare affiliated interventions, 10 of which were published in the United States and 4 in Canada. Most evaluations were observational, and only 2 used a randomized controlled trial (RCT) design. We identified intervention strategies across patient, clinic, and systems levels—most studies employed strategies at multiple levels. The most common patient-level strategies were case management, material assistance, evidence-based interactions, and health education. The most common clinic-level strategies were multidisciplinary teams, population-specific employee training, and established referral relationships with partner agencies. The most common system-level strategies were data sharing and patient monitoring technology. Studies used a range of approaches to integrate primary care with other services for this patient population, including co-location, interdisciplinary care planning, standard referral, and enhanced referral. In particular, the ACCESS program sough to integrate social and medical care for persons with experiences of homelessness and mental illness through formalizing and growing cross-agency linkages. For some studies, the description of primary care engagement was limited and difficult to categorize. Programs that had the highest degree of complexity generally included multiple intervention components, targeted a range of behaviors, were highly flexible, required additional staff training, and intervened across multiple service sectors. Most programs did not require program participants to have a high level of skill to participate despite the complexity of the targeted behaviors.

## PRIOR SYSTEMATIC REVIEWS

Prior systematic reviews evaluated interventions for patients with SMI or who had experienced homelessness, but did not explicitly address the intersection of patients with experiences of homelessness [underlined: and] SMI. Health Quality Ontario (2016)^14^ reviewed 5 studies to identify interventions that improved access to a primary care provider for people with experiences of homelessness. Two studies included Veterans and 3 studies identified high rates of mental illness in their study populations. Intervention strategies identified included orientation to the clinic, outreach, primary care integration into homeless services, and housing and supportive services; however, interventions were complex and included multiple components. The authors concluded that orientation to clinic services may improve access to a primary care provider, but in general evidence was of low quality. Jego and colleagues (2018) aimed to describe which primary care programs offer care to populations experiencing homelessness.^15^ That review included 19 studies of any design. Only 1 of these studies was included in the Health Quality Ontario review.^52^ Jego et al found that most programs were complex and included multidisciplinary team-based and integrated-care approaches. The results from both reviews about the importance of clinic orientation as a strategy to improve access to health care emerged from 1 RCT by O’Toole et al; clinic orientation was a treatment arm that comprised a personal health assessment and brief in-person introduction to the clinic. We did not find any studies that used this strategy in our evidence map. Similar to the findings of these prior reviews, we identified organizational strategies in studies with clearly defined homeless and mental illness samples. Interventions usually had multiple components and almost always relied on some level of multidisciplinary interaction among health and social service providers.

A 2011 systematic review conducted by the Durham VA ESP examined care models to improve health outcomes of individuals with serious mental illness, though primary care engagement was not the direct outcome of interest. Bradford and colleagues (2011) identified 7 papers, of which 4 were RCTs (n=3 in Veterans) that met study criteria.^53^ The review found that most models were implemented in mental health specialty settings and relied on care management or care coordination strategies. Integration elements of the patient-centered medical home were not always clearly implemented. Our evidence map findings align with the findings of that systematic review in that we also identified care coordination and care management as commonly used strategies. Some of the studies we reviewed assessed strong models of integration, though in some studies models were not well described. Our evidence map advances current understanding for populations with an overlap in experiences of homelessness and mental illness. We benefitted from the organizational structures and components suggested by prior reviews, and we are able to disaggregate intervention components at multiple levels to understand patient, clinic, and organizational factors. However, none of the other reviews used a standardized approach to evaluate intervention complexity—our evidence map thus contributes to the literature in this unique way.

## CLINICAL AND POLICY IMPLICATIONS

Our evidence map identified studies evaluating interventions which sought to promote primary care engagement among patients with experiences of homelessness and SMI, most of which had interventional elements occurring at 3 distinct levels (ie, patient, clinic, system). The included studies demonstrated heterogeneous approaches to promotion of primary care engagement, and it was clear that no single approach has been applied universally. While an evidence map is not intended to draw conclusions about which intervention approaches result in improved outcomes, our findings offer some implications for clinical and health policy groups charged with improving the care of this patient population. First, our study identifies and categorizes elements that have been employed in various combinations to improve primary care engagement among this target population. Health care systems, federal agencies, and nonprofits seeking to initiate or build similar programs could use our mapping of multi-level strategies to develop their intervention approach and ensure in-depth consideration of a variety of patient-facing clinic structure and interagency approaches. Second, our description of intervention complexity of the included studies could guide new programs in this area about the ways their intervention design places demand on different dimensions of structural and person-level components. Moreover, existing programs could compare their program components against the examples described in this report to ensure that potential dimensions of complexity are both purposefully addressed and articulated for ideal communication. Finally, our outcome mapping can help programs for patients with SMI and housing insecurity consider the breadth of approaches to measuring program effectiveness and identify the strongest outcome.

Within the VA health care system, there are numerous rich resources both for complex mental health illnesses such as SMI and for individuals who are experiencing homelessness or housing security. For example, the VA offers a collaborative primary care model for Veterans who experience homelessness; these clinics co-locate staff with expertise in mental health, substance use, medical care, and homelessness support. Separately, the VA offers a Mental Health Intensive Care Management Program (MHICM) which helps Veterans with SMI live in the community through intensive case management; however, this program is not integrated with primary care. The VA is also testing an SMI PACT for individuals with SMI whose psychiatric symptoms can be managed in primary care with consultation from mental health and psychiatry services^54^ and offers evidenced-based programs to help Veterans integrate into the community and earn an income through supported employment, which historically has focused on Veterans with SMI.^55^ However, these resources often operate separately, and as a result, individuals who are part of this target population might fall through the cracks. Yet the existing resources offered by the VA could support the development of integrated population-specific programs that pool collective efforts in a patient-centered manner and that require less navigational and engagement skills from the patients themselves. Intentional program development with attention to intervention complexity and strategy choice could also inform the appropriate choice of outcome measures.

## LIMITATIONS

This evidence synthesis should be interpreted in the context of several limitations, which are outlined in the following paragraphs.

### Study Quality and Design

We found 1 significant limitation of the existing literature considered for this evidence map in the lack of studies designed to determine the effectiveness of care models focused on connecting patients with SMI and experiences of homelessness to primary care. While not surprising, much of the identified literature comprised non-comparative, 1-armed evaluations using varying approaches to assess outcomes. Moreover, many of the included interventions were not singularly focused on promoting primary care engagement. It is likely that there are additional programs in practice that have attempted to connect patients with SMI and experiences of homelessness to primary care but that have not been described in the peer-reviewed literature. We also found few pragmatic trials or implementation studies that would be helpful to inform future implementation of novel programs to support this patient population.

In addition, we found a wide variety of outcome measures used across studies without a consistent outcome for primary care engagement. This may have occurred because many of the studies were not focused on primary care engagement, or at least did not have this as a primary aim, as we included studies that may not have been designed for the express purpose of assessing our outcome of interest. However, given that patient engagement with primary care occurs across a spectrum, from initial appointment scheduling to longitudinal interaction for chronic disease management, the field would benefit from clearly defined, patient-oriented, and clinically meaningful outcomes. In particular, further investigation is warranted to link programmatic elements with concrete outcomes and guide future development of programs. In addition to examining the impact of individual elements on outcomes, it is important to understand how the inclusion of elements at each level, and their interaction, are received by both patients and providers of services. For example, experience of homelessness (ie, street homeless vs housing instability) could moderate intervention effects, but few studies considered patient-level moderators. Given the range of outcomes evaluated, it is difficult to determine whether this length of time is sufficient to capture meaningful change in the constructs measured. From a broad perspective, there appears to be a lack of consistency in research in populations experiencing homelessness as to what constitutes “housing stability” or “tenancy sustainment”, which can make it challenging to systematically evaluate what interventions are necessary, and for how long, to achieve health- and stability-related outcomes.^56^ Finally, no outcome measures were clearly validated or designed for the specific patient population of those with experiences of homelessness.

### Intervention Strategy Reporting

We encountered challenges with the identification and interpretation of intervention strategies. In addition, the depth and detail provided about the intervention itself was generally insufficient for determining the level of integration using validated tools or for fully facilitating replication.^27^ Types of information that we might recommend other program designers and evaluators report include the extent to which behavioral and medical providers are involved in clinical decision-making. Moreover, some included studies only provided details on a few specific intervention components, and thus it is possible that additional components were employed and just not described. For example, informal interagency or multi-sector collaboration agreements to facilitate referrals or shared resources may have been leveraged but not explicitly reported. No included studies reported using a theoretical model to guide intervention or program development or described potential mechanisms of effect. Additionally, we only found studies that focused on the pathway of engaging patients with SMI and housing insecurity to primary care, and none that were developed to provide or enhance services to patients already in primary care who develop housing insecurity or destabilizing of their SMI.

It is important to note the limitations of our approach to this evidence map as well. First, we limited our eligibility criteria to those studies that were either clearly intended for patients with SMI or met our criteria for SMI through other diagnoses. It is possible that we excluded studies that did not explicitly report serving a majority of patients with SMI and thus missed some potentially relevant literature. Second, we categorized intervention strategies according to our understanding of the target of the strategy itself (patient, clinic, or system). Some strategies, such as assertive community treatment, could be considered to target multiple levels, and others might have been categorized differently. Third, we chose to use the iCAT-SR, a state-of-the-art approach to classify complex interventions. Despite using this methodologically strong approach, other ways of examining this aspect of the literature (eg, TIDIER ^57^) may have produced dissimilar results.

### Generalizability and Applicability of Findings to the VA Population

While patient populations represented in this evidence map are likely similar to Veterans with SMI and housing insecurity, the majority were not conducted in VA clinical settings (only 2 were in the VA^37,45^). Yet most of the interventions described rely heavily on local resources and collaborative agencies to supply the complex and multifaceted health and social support needed, and the VA has many similar system-level offerings that could be brought to scale to address the primary care health needs of this population. For example, the VA is an integrated health and social service system that has a common medical record, robust homeless support services, co-located behavioral and physical health care, and primary care providers with training in evidence-based patient interactions like motivational interviewing. However, coordinating across these sectors in the VA is still a challenge,^58^ and as with most interventions, these services address SMI and experience of homelessness as distinct vulnerabilities. Therefore, there are opportunities to improve current services by implementing clinic- and patient-level strategies for individuals with both conditions using consistent outcome measurement to assess their effect on primary care engagement.

## RESEARCH GAPS/FUTURE RESEARCH

As 1 purpose of an evidence map is to identify gaps in the literature, here we consider areas that future work might address. First, we found only 1 study that enrolled patients directly from the criminal justice system. Given that this patient population has high levels of justice involvement, focusing on connecting with patients in this area would be valuable. Second, many of the included studies focused solely on either the initial connection with primary care or providing integrated care for acute issues. Attention to the longitudinal relationship of maintaining primary care engagement for this population will be crucial for improving long-term health outcomes. Third, additional validation of outcome measures across the spectrum of primary care engagement used consistently across studies and program evaluations would support comparisons and summary of effectiveness. Fourth, while randomized controlled trials are the gold standard for efficacy intervention evaluations, they are unlikely to be appealing or feasible in this context. Well-conducted stepped wedge design pragmatic trials could offer a rigorous approach to evaluating future interventions for this population. On a brief review of clinicaltrials.gov, no studies focused on patients with SMI and experiences of homelessness were identified, though there were a small number of studies focused on chronic medical conditions among patients with SMI (eg, diabetes, obesity, cardiovascular risk). Given the level of complexity needed to care for the target population, adaptive studies that build in ways to test various components and outcomes would constitute another potentially useful methodological approach. Relatedly, few studies employed rigorous implementation science methods. Most interventions were localized without a demonstrated vision for scaling up the effective components. Implementation science will be essential to understanding barriers and facilitators to implementation and how these interventions need to be adapted for broader scale up and dissemination. Table 11 outlines multiple other areas for consideration for future intervention strategy testing.

Table 11 Evidence Gaps and Areas for Future Research Consideration

Population
- Patients with SMI and experiences of homelessness identified through the criminal justice system
Interventions
- Interventions designed to follow patients throughout the spectrum of primary care engagement, including longitudinal follow-up; - Optimal team composition and collaboration for interdisciplinary approach (eg, how primary care teams should differ when engaging this population); - Embedding technologies related to proactive monitoring and care coordination); - Identifying implementation strategies to facilitate adoption of evidence-based interventions; - Identification of evidence based “core components” of multicomponent interventions; - Theory-based interventions
Comparators
- Various models of primary care integration approaches; - Different clinical and community settings or health care systems; - Across important subpopulations for which programs might be more effective than for others
Outcomes
- Validated measures of primary care engagement across the spectrum of engagement from initial visit to longitudinal care; - Cost effectiveness; - Patient-reported outcomes
Setting
- Long-term housing support program; - Rural communities; - VA-based health care systems

## CONCLUSIONS

Individuals with SMI and housing insecurity often have chronic, complicated health needs. Addressing these health needs requires population-tailored interventions to promote longitudinal primary care engagement. We mapped the breadth of literature seeking to engage this patient population with primary care, including those interventions focused at the individual clinic level to national multi-site demonstration projects. In general, studies did not focus on primary care engagement as a primary outcome. We found that programs typically employ multiple intervention strategies, usually across patient, provider, and system levels. While not always well-described, the approaches used to engage patients with primary care could involve co-location with other service disciplines, interdisciplinary care planning, and enhanced and standard referral processes. Organizations seeking to optimize the health care of this vulnerable patient population can use this map to inform program strategy choices during development and reevaluation. This literature could be improved by rigorous study designs to evaluate the effectiveness of interventions, standardized descriptions of intervention components sufficient for replication and full characterization, and a uniform and validated approach to measuring primary care engagement. As one of the nation’s largest integrated health care providers, the VA may be in a unique position, given its robust history of addressing the needs of Veterans experiencing homelessness, collaborative mental health care programs, and patient-centered medical home model, to consider tailoring and developing new programs for patients with SMI and housing insecurity incorporating the considerations noted above.^59^