# RESULTS

## LITERATURE FLOW

We identified 7,897 studies through searches of MEDLINE® (via Ovid®), EMBASE, and PsycINFO (Figure 2). An additional 7 articles were identified through reviewing bibliographies of relevant review articles for a total of 7,904 articles. After removing duplicates, there were 4,650 articles. After applying inclusion and exclusion criteria to titles and abstracts, 191 articles remained for full-text review. Included studies were conducted across Canada and the United States. Two studies were conducted within the VA.

Figure 2 Literature Flow Chart

*Search results from Ovid MEDLINE (3,358), EMBASE (942), PsycINFO (343), and identified from relevant articles (7) were combined.

## KEY QUESTION 1 What intervention strategies have been studied among adults with experiences of homelessness or who are at high risk of experiencing homelessness and who have serious mental illness (SMI) to promote engagement in primary care?

### Key Points

- Interventions designed to promote engagement in primary care for adults with experiences of homelessness or who are at high risk of experiencing homelessness and have SMI often employ multi-level strategies (eg, at the patient, clinic, and system levels).
- The most frequently described patient-level strategies include health education, service navigation, material housing support, and interdisciplinary needs assessment.
- Population-specific employee training was the most common clinic-level strategy, while psychiatry, primary care, and care management were the most frequently described disciplines delivering the intervention strategies across included studies.
- System-level strategies include shared documentation and record systems (eg, electronic health records and social services administrative records), standardized performance metrics, and a proactive monitoring system.
- There was a relatively even distribution of the 4 key elements of practice integration across included studies, including co-location of primary care with other disciplines, interdisciplinary care planning, a network of established referral pathways built to support interactive communication, and standard referral mechanisms.

### Detailed Findings

We identified a total of 22 articles describing 15 different interventions and programs designed to support primary care engagement among patients with housing insecurity and SMI.^28–49^ Seven of the 22 included articles describe the ACCESS demonstration project,^38–44^ which we discuss separately from the other 14 individual interventions and programs.

#### ACCESS Characteristics and Demographics

The Access to Community Care and Effective Services and Support (ACCESS) was a federal demonstration program initiated in 1993. It was developed in response to recommendations from the Federal Task Force on Homelessness and Mental Illness, which sought to address the barriers generated by fragmented and isolated service delivery systems.^38–44^ Endorsed and funded by the US Department of Health and Human Services, the goal of ACCESS was to test the effectiveness of systems integration strategies hypothesized to support patients with experiences of homelessness and mental illness by improving coordination across the social and medical care continuum. The ACCESS program was implemented at 18 sites in 9 pairs across major cities in the United States; all sites were provided financial resources to enhance services, but only 9 were given additional funding to support system integration.

We identified 7 publications that evaluated different aspects of the ACCESS multi-site comparative program evaluation and which included reference to primary care as a component of system integration (see Table 2 and Appendix B).^38–44^ Included ACCESS analyses were published in the 11 years spanning 1997 to 2008 and examined outcomes at the patient level (eg, physical and mental health status, health care utilization), clinic level (eg, patient referrals), and system level (eg, agency linkages and system coordination). One study compared the impact of gender on the outcomes of the ACCESS program.^38^ Included studies examined data across ACCESS sites (all but one^41^ from all 18 different sites around the country. Four studies (57%) reported the source of patient enrollment, which included locations such as homeless shelters, the streets, drop-in centers, service agencies, and soup kitchens, among others.

Individual participants at ACCESS sites were required to be homeless (had spent at least 7 of the past 14 nights in a shelter, outdoors, or in a public or abandoned building); have severe mental illness (psychiatric eligibility was determined with a 30-item screening algorithm); and not be involved in ongoing mental health treatment. Two studies reported patient-level demographics.^38,43^ Both reported patient mean age as 38.5 years. One study reported the racial/ethnic make-up of patients, with 44.5% Black and 5.2% Hispanic.^43^ One study reported mean monthly income of $328 (standard deviation, $449).^43^ No study reported patient employment status. One study reported a 16% alcohol use disorder among patients.^38^

Table 2 Evidence Profile of ACCESS Studies (n=7)

Number of studies: 7 studies (1 intervention)
Study designs: ACCESS multisite comparative program evaluation (n=7)
Number of participants^a^: n=7,229
Enrollment setting^a^,^b^: homeless shelters, the streets, drop-in centers, service agencies, and soup kitchens, among others (3 studies NR)
Countries: 18 cities across USA (n=1)
Serious mental illness: ACCESS intervention designed specifically for patients with SMI
Housing insecurity: Participants had spent at least 7 of the past 14 nights in a shelter, outdoors, or in a public or abandoned building
Patient demographics: median age = 38 years old (5 studies NR); women (37%) (5 studies NR) race (44.5% Black) (6 studies NR)
Duration of intervention: 5-year demonstration project
Patient-level intervention domains: education/training (n= 0); evidence-based patient interactions (n=3); outreach (n=0); clinical/case management (n=5); structural/material supports (n=4); low-barrier clinic approaches (n=1)
Clinic-level intervention domains: program staff support (n=4); specialized team members (n=0); clinical offering domain (n=0)
System-level intervention domains: data sharing infrastructure (n=4); evaluation (n=0); coordination approaches (n=3)
Primary outcomes reported: system integration (n=3); health status (n=1); other (n=1) (2 studies NR)^c^

a Not all ACCESS studies analyze data from full cohort

b Studies recruited from multiple locations

c Studies reported more than one primary outcome

#### Non-ACCESS Study Characteristics and Demographics

We identified 14 interventions to improve access to primary care for individuals with SMI experiencing homelessness (see Table 3 and Appendix B).^28,30–37,45–49^ Study designs included cohort studies (n=4^28,36,45,47^), program evaluations (n=4^32,35,48,49^), controlled before-after studies (n=2^34,37^), randomized controlled trials (n=2^31,33^), a cross-sectional study (n=1^46^), and a qualitative study (n=1^30^). Twelve studies (86%) reported participant-level enrollment.^28,30–34,36,37,45–47,49^ Of 12 studies reporting, 10 studies (83%) included 500 or fewer participants,^28,30–34,36,37,46,49^ 1 study had 501-1000 participants,^47^ and 1 study had more than 1000 participants.^45^ Eleven studies (79%) reported participant sex^28,30–37,45–49^; 10 studies enrolled mostly men in the intervention group (range 62.6% to 100% male),^28,30,33–37,45,46,49^ and 1 study reported a slight minority of men in the intervention group (45% male).^31^ All 5 studies with comparison groups reported majority male samples (range 56% to 100%).^28,31,34,36,37^ Of the 10 studies (71%) reporting age of participants, the mean age range was 38.6 to 52.9 years.^28,31,33–37,45,46,49^ Four studies (28%) were majority white, ^28,31,34,45^5 studies (36%) were majority Black,^33,35,37,46,49^ and 1 study reported most participants were of Hispanic ethnicity.^36^ Four included studies (28%) did not report the racial/ethnic make-up of participants.^30,32,47,48^

All 14 interventions were conducted in either the United States (n=10, 71%)^30–33,35–37,45,46,48^ or Canada (n=4, 28%)^28,34,47,49^. While targeting patients with housing insecurity, 9 studies (64%) did not report specific baseline housing status of participants; 1 study (7%) reported number of nights spent on streets or in shelters in past 12 months^34^; 1 study (7%) reported situational (ie, episodic) versus chronic homelessness^36^; 1 study (7%) reported whether or not individuals were in transitional housing^30^; and 1 study (7%) reported whether individuals lived in transitional housing (supervised or temporary shelters) or had a primary nighttime residence not meant for human habitation.^31^

Table 3 Evidence Profile of Non-ACCESS studies (n=15)

Number of studies: 15 studies (14 interventions)
Study designs: randomized controlled trial (n=2); controlled before and after (n=2); cohort (n=4); program evaluation (n=4); cross-sectional (n=1); qualitative (n=1)
Number of participants: 3,945 (2 studies NR);
Enrollment setting^a^: housing services (n=7); clinical setting or a multidisciplinary program (n=5); criminal justice (n=2); soup kitchen (n=1); drop-in service center (n=1); outreach team (n=1); setting not reported (n=4)
Countries: USA (n=10); Canada (n=4)
Serious mental illness: explicitly designed for patients with SMI (n=11); 75% or more patients meeting broad definitions of SMI (n=7)
Housing insecurity: all studies targeted patients with housing insecurity; number of nights on the street (n=1); situational vs chronic homelessness (n=1); transitional housing (n=2); specific housing status not reported (n=9)
Patient demographics: median age = 44 years old (2 studies NR); women (10%) (6 studies NR); race (51% White) (10 studies NR) (50% Black) (8 studies NR)^b^
Duration of intervention: median duration was 12 months range (6 weeks to 2 years) (6 studies NR)
Patient-level intervention domains: education/training (n= 5); evidence-based patient interactions (n=9); outreach (n=4); clinical/case management (n=13); structural/material supports (n=10); low-barrier clinic approaches (n=6)
Clinic-level intervention domains: program staff support (n=18); specialized team members (n=7); clinical offering (n=3)
System-level intervention domains: data sharing infrastructure (n=9-4); evaluation (n=2); coordination approaches (n=0)
Primary outcomes reported: healthcare utilization (n=4); health status (n=3); other (n=3) (5 studies NR)^c^

a Studies recruited from multiple locations

b Only 2 studies report both Black and White race information

c Studies reported more than 1 primary outcome

The patient enrollment locations varied across the included studies (Figure 3.) Five studies reported recruiting from a clinical setting or a multidisciplinary program^28,31,33,48,49^; 3 of these reported also recruiting from a housing services location.^28,31,33^ Four studies reported recruiting only from housing services.^30,34,37,45^ One study recruited from the criminal justice system alone,^36^ and 1 study recruited from the criminal justice system in combination with other locations.^49^ In addition to other recruitment locations, 1 study recruited from a drop-in service center,^37^ 1 from a soup kitchen,^45^ and 1 with the help of outreach teams.^49^ Four studies did not report recruitment locations.^32,35,46,47^

Figure 3 Sources of Patient Enrollment^a^ a Studies could use multiple sources for patient recruitment ^,b^ b Does not include ACCESS studies

The included studies met our eligibility criteria for being designed for patients with SMI as follows: 11 studies were explicitly designed for patients with SMI,^30–35,45–49^ and 3 studies were not specifically designed for patients with SMI but met our criteria for including 75% or greater patients meeting broad definitions of SMI (ie, also major depressive disorder and posttraumatic stress disorder).^28,36,37^ No studies met eligibility criteria by including a subgroup analysis limited to patients with SMI or by meeting the 75% criteria with the narrower definition of SMI (ie, schizophrenia, bipolar disorder, and other psychotic disorders). Three studies explicitly designed for patients with SMI did not report characteristics of SMI for their sample.^32,47,48^ Some studies also reported comorbid conditions, primarily other behavioral and mental health conditions. For example, of the 7 studies reporting comorbid substance use, 9% to 74% of participants were identified to also have active drug and/or alcohol use.^28,34,36,37,45–47,49^

#### Intervention Strategies by Level

For KQ 1, we identified all intervention strategies described by each study and categorized each individual strategy according to its targeted level of action: patient, clinic, or system. Intervention strategies identified were not restricted to those pertaining to primary care engagement. To organize these findings, we grouped intervention strategies within level into domains (see Figure 4). Across all included studies, we identified 22 patient-level intervention strategies across 6 domains; 4 clinic-level intervention strategies across 3 domains; and 5 system-level strategies across 3 domains (see Figure 5). Four studies included strategies at all 3 levels,^31,32,34,35^ and 1 study included strategies on only 1 level.^45^ All studies used at least 2 patient-level strategies, and the total number of strategies described ranged from 2 to 11. Additionally, we found 6 different disciplines that compromised the core intervention staffing and 7 types of collaborating agencies typically partnered with for additional services. Next, we describe reported intervention strategies at each of the 3 levels. The median duration of these intervention was 12 months and ranged from 6 weeks to 2 years,^28,30,31,33,37,46,47,49^ although 6 studies did not report this information.^32,34–36,45,48^

Figure 4 Framework of Multi-Level Intervention Strategies

Figure 5 Studies per Domain at Patient, Clinic, and System Levels

##### Patient-level Intervention Strategies

Included studies employed a variety of intervention strategies which directly targeted patients, which we organized into 6 domains (ie, education/training, evidence-based patient interactions, outreach, clinical/case management, structural/material supports, low barrier clinic approaches). The most frequently described patient-level strategies were health education (5 studies), motivational interviewing (5 studies), interdisciplinary intake (7 studies), service navigation (6 studies), and material assistance for housing (9 studies) (Table 4). Interdisciplinary needs assessment and service navigation typically emphasized the uptake of services based on enhanced referral pathways to community-based organizations, social services, or specialized medical services. Additionally, 14 studies featured material supports by providing housing, access to technology, income assistance, and food assistance programs.^30,31,34–37,39,40,42,44–47,49^ This included but was not limited to studies that incorporated the “Housing First” program model, which prioritizes permanent, stable housing with supportive services, including linkages to non-mandated health services.^50^ Eleven studies incorporated evidence-based therapies or interactions to improve patient-provider collaboration as an intervention component.^28,30–33,36,39,40,44,48,49^ The most frequently described of these techniques were motivational interviewing (5 studies), empathic/stigma reducing communication (4 studies). Eight studies included health education as an intervention component, often emphasizing chronic disease self-management, navigating the health care system, partnering with the care team, and social support.^30–34,36,49^ For example, Stergiopoulos et al and Stanhope et al both described the role of patient education that is responsive to both social and medical drivers of health by leveraging peer and social support.^30,49^ Additionally, 4 studies included crisis intervention as an available mechanism for a short-term intensive response.^32,39,48,49^ Baker et al describe a nurse practitioner-driven program that offered crisis services as a strategy to avoid unnecessary hospitalizations, incarceration, or a return to homelessness.^32^ Finally, 7 studies described strategies to facilitate uptake of medical services by reducing clinic barriers.^30,32,34,35,37,44,46^ These strategies included reducing eligibility requirements (eg, no requirements for sobriety or substance use treatment to participate), wait times, appointment prioritization, and by embedding the clinic location within the target community. Importantly, interventions often combined strategies to enhance effectiveness. For example, Kelly et al describe how health education, case management, and evidence based patient interactions can be delivered in conjunction as a multi-component self-management intervention.^31^ It was delivered as a manualized, peer-led intervention using motivational interviewing, cognitive behavioral strategies, and psychoeducation about the healthcare system, benefits, health screenings, and working with medical providers.

Table 4 Patient-level Intervention Strategies by Domain

Intervention Strategy | Definition | Study
Education/Training domain
Health education | Provide learning on health topics including navigation of the health system, ways to reduce barriers to care, health promotion/disease prevention strategies, and information about specific health conditions | Non-ACCESS^30,31,35,36,49^
Patient-provider communication techniques domain
Motivational interviewing/ goal-setting | Building motivation for behavior change and/or engaging in realistic development of goals and plans to meet them | Non-ACCESS^30,31,33,36,49^
Trauma-informed care | A care approach that acknowledges the impact of trauma history and seeks to promote appropriate responses and avoid retraumatization | Non-ACCESS^33^
Empathic/stigma reduction | An approach that seeks to act with empathy for an individual’s state and reduce shame/negative associations associated with conditions or seeking care | ACCESS^44^; Non-ACCESS^36,48,49^
Supportive therapy | A form of psychotherapy that emphasizes the importance of the relationship between provider and patient in order to alleviate symptoms and address challenges | Non-ACCESS^28^
Cognitive behavioral therapy | A form of psychotherapy focused on addressing unhelpful beliefs and behaviors to improve symptoms | Non-ACCESS^31^
Other therapies | Unspecified therapeutic interventions | Non-ACCESS^32^
Assertive community treatment | A multidisciplinary team approach which provides direct psychiatric care in the community, engages in assertive outreach, and offers rehabilitation and support services | ACCESS^39,40^; Non-ACCESS^30,35^
Harm reduction | A public health philosophy and accompanying set of practices and principles aimed at reducing harms associated with drug use and drug policies, as opposed to focusing on a traditional approach of abstinence promotion | Non-ACCESS^33,49^
Outreach domain
Assertive outreach | An intensive mental health services approach for individuals with serious mental illness that aims to promote engagement in the health care system | Non-ACCESS^28,35,46^
Hospital in-reach | An outreach approach that works with hospitalized individuals to support discharge transitions, connect them with services, and reduce unnecessary rehospitalization | Non-ACCESS^28^
Justice system inreach | A case management approach that seeks to support incarcerated individuals who are being released to connect with health care services | Non-ACCESS^36^
Clinical/case management domain
Crisis intervention | Immediate, short-term emergency response for a distressed individual | ACCESS^39^; Non-ACCESS^32,48,49^
Interdisciplinary intake/needs assessment | Intake assessment/evaluation approach that engages multiple specialties (eg, psychiatrist, physician, case manager) with a focus on the patient’s individuals needs | Non-ACCESS^28,31,32,35–37,49^
Service navigation | Linking patients and reducing barriers to essential health and community services and resources and/or coordinating these services | ACCESS^39,40,42–44^; Non-ACCESS^28,30–37,45,46,49^
Transitions of care coordination | Coordination among health care providers as a patient changes providers or settings | Non-ACCESS^36^
Structural/material supports domain
Transportation | Assistance for transportation in the form of dedicated financial support or items that support transportation (eg, bus pass) | Non-ACCESS^37^
Food | Money provided for the purchasing of food | Not applicable
Housing | Money provided toward temporary or permanent housing | ACCESS^40,42,44^; Non-ACCESS^30,34–36,45–47,49^
Income/entitlement | Instrumental assistance in the procurement of financial or entitlement benefits | ACCESS^39,40,42,44^; Non-ACCESS^47^
Access to computers/ technology | Hardware made available for the use of participants | Non-ACCESS^31^
Low-barrier clinic approaches domain
Appointmentprioritization | Ranking incoming referrals to prioritize a certain category of patients for available appointments | ACCESS^44^; Non-ACCESS^37^
Flexible appointment scheduling | Offering appointment scheduling in a way that allows greater flexibility than a typical scheduling process, which can include off-hours or extended hours access and walk-in or on-demand appointment scheduling (eg, extended hours/24-hour access) | ACCESS^44^; Non-ACCESS^32,35,37^
No waiting times | Reducing or eliminating waiting times for appointment scheduling | ACCESS^44^; Non-ACCESS^37^
On-site at shelter | Services available at location of temporary housing shelter | Non-ACCESS^34^
Reasonable costs | Not defined by author | ACCESS^44^
No sobriety/ treatment requirements | Specifically notes lack of requirement of sobriety or substance use treatment engagement for program participation. | Non-ACCESS^30,46^

##### Clinic-level Intervention Strategies

All of the included studies contained a clinic-level intervention strategy. The most frequently described clinic-level strategy was population-specific employee training (n=9 studies). We also found that most studies leveraged a multidisciplinary team structure through interdisciplinary intervention staffing and established relationships with collaborative agencies to supplement internal resources (Tables 5–7). Nine studies (12 articles, 4 ACCESS) included training beyond what is required for discipline-specific licensure.^31–34,36–39,41,43,48,49^ Training and workforce development strategies focused on skills and techniques that are tailored to the complex patient population of interest. For example, the Jefferson Department of Family and Community Medicine and a Housing First agency, Pathways to Housing-PA, formed a partnership to serve patients with experiences of homelessness and SMI and required a homeless health training rotation to develop skills specific to this population.^46^ Training and workforce development strategies were often linked to intervention strategies at the system or patient/delivery level. An illustrative example is “cross training” for programs in the ACCESS study that emphasized system integration to ensure personnel were familiar with services and procedures from partnering agencies to fully leverage service agreements that facilitated coordination and collaboration.^38–44^ We found significant variation in the composition of intervention staffing, with the most commonly represented disciplines being psychiatry, behavioral health, nursing, social work, primary care, and peer support/community health workers. This was in contrast to interventions that utilized referral networks to obtain support outside of core program offerings (eg, referrals to community-based shelters).

Table 5 Clinic-level Intervention Strategies by Domain

Intervention Strategy | Definition | Study
Program staff support domain
Specific employee training | Training related to intervention objectives that is not necessarily part the employee’s disciplinary training (ie, motivational interviewing, stigma reduction) | ACCESS^38,39,41,43^; Non-ACCESS^31–34,36,37,48,49^
Specialized team members domain
Medical scribes | A person or paraprofessional who specializes in charting physician-patient encounters in real time, such as during medical examinations | None
Peer support/ community health workers | An individual based in the community who promotes health and wellbeing through liaison activities between health care agencies and the community, or provides social assistance and guidance to community residents | Non-ACCESS^28,30,31,33,35,36,48^
Clinical offering domain
Medication review/ management | Provider team assesses the combination of over-the-counter and prescription drugs used by an individual to be sure they are safe and effective | Non-ACCESS^31,32,35^

Table 6 Clinic-level Staffing by Discipline

Intervention Strategy | Definition | Study
Behavioral health | Psychologist, licensed clinical social worker (LCSW), therapist | Kelly, 2018^31^; McGuire, 2009^37^; Patterson, 2012^47^; Rivas-Vazquez, 2009^36^
Psychiatrist | Physicians trained in psychiatry, psychiatric/mental health nurse practitioners | Baker, 2018^32^; Kelly, 2018^31^; McGuire, 2009^37^; Patterson, 2012^47^; Solomon, 1988^48^; Stergiopoulos, 2012^49^; Stergiopoulos, 2015^34^; Weinstein, 2013^35^; Weinstein, 2013^46^
Nursing | Nurses without prescribing privileges of any training level or not otherwise specified | ^a^Baker, 2018^32^; McGuire, 2009^37^; Patterson, 2012^47^; Rosenheck, 1993^45^; Solomon, 1988^48^; Weinstein, 2013^35^; Weinstein, 2013^46^
Primary care provider | Physicians trained in primary care, primary care nurse practitioners/physician assistants | McGuire, 2009^37^; Patterson, 2012^47^; Rivas-Vazquez, 2009^36^; Solomon, 1988^48^; Stanhope, 2014^30^; ^b^Stergiopoulos, 2015^34^; Weinstein, 2013^35^; Weinstein, 2013^46^
Pharmacist | | None
Case manager/ social worker (not as LCSW) | Outreach/other shelter staff | Kelly, 2108^31^; McGuire, 2009^37^; Rivas-Vazquez, 2009^36^; Rosenheck, 1993^45^; Rosenheck, 1997^43^; Solomon, 1988^48^; Stergiopoulos, 2012^49^; Stergiopoulos, 2015^34^; Weinstein, 2013^35^
Housing services | Short-term and long-term | Kelly, 2018^31^

a Study included nursing students

b Study includes 2 separate models of care: 1 involves on-site psychiatry which is embedded into an integrated, interdisciplinary team with primary care; in the second model, there is psychiatry available on-site but primary care is accessed via neighboring clinics

Table 7 Collaborative Agencies for Services Outside Core Intervention Offerings

Intervention Strategy | Study
Behavioral health/psychiatry | ACCESS^41^; Non-ACCESS^28,30–32,34,45,46,49^
Medicine | ACCESS^41^; Non-ACCESS^28,31,32,34,45,46,49^
Social work/case management | ACCESS^40,41^; Non-ACCESS^28,31,32,45^
Long-term housing services | ACCESS^41^; Non-ACCESS^30,32,35,36^
Temporary housing services | ACCESS^41^; Non-ACCESS^32,35,36,45,48^
Pharmacy | Not applicable
Senior living center | Non-ACCESS^30^
Vocational | Non-ACCESS^49^

##### System-level Intervention Strategies

Intervention strategies employed at the system level sought to improve multi-sector coordination, information exchange, and evaluation. The most frequently described system-level intervention components included shared electronic health record (n=4) and proactive patient monitoring technology infrastructure (n=3) (Table 8). These systems were used to improve communication, documentation, and care management. Similarly, proactive monitoring systems were also used to anticipate patient needs and tailor the approach. Kelly et al evaluated a peer-delivered health navigator model that incorporated the use of a collaborative electronic personal health record to address challenges for this population related to paper record keeping.^31,51^ This type of health record and electronic monitoring system and systems like it were used to organize care delivery, anticipate patient needs, and facilitate communication between the patient and service providers—an example of how organizations promoted interagency collaboration. We found 3 articles (all ACCESS studies) that included interagency collaboration as a system-level strategy.^39–41^ Of note, this system-level strategy may have been used in other studies included in the analysis but was not explicitly referenced. Finally, we found 2 studies that reported using shared, standardized performance metrics to evaluate effectiveness across agencies and clinics.^46,47^ An illustrative example of both interagency collaboration and shared performance metrics is the intervention described in Patterson et al to improve outcomes for adults with SMI who are chronically homeless in British Columbia.^47^ Shared performance metrics included increased use of primary care, decreased hospital lengths of stay, decreased interactions with the criminal justice system, and increased use of income assistance. The authors also describe a common monitoring framework to ensure fidelity and standardization across sites in a system as part of an overarching interagency collaboration.

Table 8 System-level Intervention Strategies

Intervention Strategy | Definition | Study
Data sharing infrastructure
Shared electronic health record | Collaborating agencies use common electronic health record (EHR) for care and management of patients | Non-ACCESS^31,32,34,46^
Proactive monitoring system | Collaborating agencies use common electronic database for monitoring of patient needs in order to anticipate needs | ACCESS^38,39,41^; Non-ACCESS^31,35^
Shared social services administrative record | Collaborating agencies use common administrative system for documentation of case management | ACCESS^39,44^
Evaluation
Standard performance metrics | Agencies or clinics caring for patients report use of standard quality measures to evaluate and monitor care provided | Non-ACCESS^46,47^
Coordination Approaches
Interagency collaborative body | A multidisciplinary group established to support ongoing interactions between agencies supporting the target population | ACCESS^39–41^

##### Access to Community Care and Effective Services and Supports (ACCESS)

In addition to the system-level intervention strategies noted above which were reported in the included articles, the ACCESS federal demonstration program also established a set of specific system integration strategies for use across its sites. Systems integration refers to efforts to improve service system for a defined population rather than for individual patients. System integration is a continuum of combined strategies at the system, clinic, and patient/delivery levels, ranging from information sharing and communication to full-service delivery integration (Table 9).^41^ As a part of ACCESS, participating sites were provided funding to facilitate adoption of a range of system integration strategies that were selected and tailored to their local context. As such, each site could have employed different combinations of strategies. While in the preceding tables, we identified individual strategies reported in included ACCESS papers. Below, we share the overarching range of potential system integration strategies used at each ACCESS site.

Table 9 ACCESS: Potential System Integration Strategies^a^

ACCESS Strategy | Definition | Intervention Level
Co-location of services | A multiservice center in a single location to facilitate access to medical services, substance abuse treatment, housing assistance, entitlement programs, or financial assistance. | Clinic
Systems integration coordinator position | A staff position focused on implementing systems integration activities. These responsibilities include engaging stakeholders, staffing interagency coalition meetings, acting as a liaison to other systems, and coordinating joint proposal or service contracts. | Clinic
Cross-training | The training of staff on procedures and services available at other agencies. This can include training staff to utilize agreements to collaborate, accept referrals, coordinate services, or share patient information. | Clinic
Interagency service delivery team | A service delivery team that is composed of interdisciplinary staff from 1 or more agencies. The teambased approach is designed to address the complex patient needs in an integrated manner. | Clinic
Interagency coordinating body | An advisory group composed of representatives from multiple agencies to address common challenges including formal agreements to reduce barriers to services, eliminating duplication of services, and promoting access. An interagency coordinating body can be established at local or state level. | System
Interagency agreements | Formal or informal agreements among agencies to coordinate, collaborate, or offer combined services. | System
Joint funding | A broad array of agreements or arrangements to combine funding to offer additional resources or support interagency initiatives. | System
Flexible funding | The designation of flexible funding sources that can be used to purchase expertise, fill gaps, or coordinate the acquisition of addition resources. | System
Use of special waivers | A statutory or regulatory waiver aimed at reducing interagency barriers to services, eliminating duplication, or promoting access. | System
Consolidation of agencies | The process of combining multiple programs or agencies under a centralized administrative structure to better integrate delivery of services across previously fragmented systems. | System
Interagency managementinformation and monitoring systems | Information tracking and management systems to facilitate transfer of patient information, simplify referral processes, reduce duplication of services or documentation, and improve access to services for patients. | System and Clinic
Uniform applications, eligibility criteria, and intake assessments | The standardization of processes used by participating agencies that potential patients must complete to apply for or receive services. | System, Clinic, and Patient

a Table adapted from Cocozza, 2000.^41^

##### Approaches to Engagement with Primary Care

We considered the elements of integration between primary care and the other services provided to patients with SMI and housing insecurity (eg, standard referral, enhanced referral, co-location and interdisciplinary care planning) across each included study (Figure 6 and Table 10). We considered the presence or absence of each element individually. Standard referral reflects the most basic mechanism for patient referrals to primary care largely driven by insurance networks and approvals. An enhanced referral was identified when a program had a clearly described, established relationship with a primary care clinic that supported interactive communication between the program providing housing services or mental services. Co-location was identified if primary care and other program services are in physical proximity with each other. Finally, interdisciplinary care planning indicates that multiple disciplines worked together to generate and carry out plans of care for individual patients.

Figure 6 Approaches to Engagement with Primary Care^a^ a There could be overlap between approaches ^b^ b Does not include ACCESS studies

Overall, we found that there was a relatively even distribution of the 4 key elements of practice integration across included studies. Four studies included evidence of both co-location and regular interdisciplinary care planning,^34,36,37,46^ while 1 additional study employed interdisciplinary care planning but primary care was not co-located.^30^ For example, McGuire et al reported on a VA-based integrated clinic in which homeless Veterans presenting to a housing program screening clinic were seen same-day by a specially trained, co-located primary care team.^37^ Three studies describe models in which primary care was co-located but there was no clear reporting that interdisciplinary care planning took place.^28,35,47^ Six studies employed enhanced referral mechanisms to connect patients with primary care.^28,32,45–48^ Baker et al demonstrated an enhanced referral process as part of a psychiatric/mental health NP-run, independent community health center which cared for individuals who were homeless or had housing insecurity due to SMI; they maintained a “robust referral system” and regular contact to primary care within local major health care systems.^32^ Four studies used a standard referral process to connect patients with primary care based on typical consult mechanisms guided by insurance networks and without the benefit of established interactive relationships.^31,33,34,49^ Note that 1 of these studies is a 2-armed study in which 1 arm features fully integrated primary care that is co-located with interdisciplinary planning and the other arm used a standard referral process.^34^ Some studies used multiple routes to connect patients with primary care; for example, Weinstein and colleagues report on a Philadelphia-based program which embedded a primary care provider from a nearby academic family and community medicine department into an existing Housing First care management team as part of an integrated care program, and also supported patients who preferred to receive primary care from a non-specific local source. Of note, for some of the included studies, the description of the connection with primary care was minimal and it is possible that included programs in practice incorporated more elements of integration with primary care than were reported in the published intervention description.

Table 10 Elements of Primary Care Integration

Intervention Strategy | Definition | Study
Interdisciplinary care planning | Multidisciplinary team (eg, medical providers, social workers, nurses) meet on a routine basis to discuss patient cases but not necessarily co-located | Non-ACCESS^30,34,36,37,46^
Co-location | Services that are located in the same physical space (eg, office, building, campus), though not necessarily fully integrated with one another (eg, mental health, primary health care) | Non-ACCESS^28,34–37,46,47a^
Enhanced referral | Existing relationships between the intervention site and community primary care, but which is not integrated into the intervention program | Non-ACCESS^28,32,45–48^
Standard referral | Intervention described as connecting patients to primary care but does not provide evidence of interactive communication with those services; this is akin to a case manager facilitating a referral to an external community based primary care clinic from which the patient may be eligible to receive services | Non-ACCESS^31,33,34,49^

a Stergiopoulos 2015^34^ includes 2 separate models of care: 1 involves onsite psychiatry that is embedded into an integrated, interdisciplinary team with primary care; 1 involves psychiatry available onsite but primary care is accessed via neighboring clinics.

### Intervention Complexity

We categorized the complexity of included interventions using the iCAT_SR tool grouped by clinic-based interventions versus system or interagency interventions (see Appendix G for study-specific iCAT_SR determinations). Among interventions focused on individual clinical programs, areas of high complexity common across studies included having multiple active intervention components that targeted a complex collection of behaviors (Figure 7). Interventions were typically highly flexible to allow tailoring of support provided to individual patients depending on their clinical and housing needs. In general, the nature of the causal pathway from the intervention to the intended patient outcome (eg, improved physical/mental health, stable housing) was often not explicitly described, but inferred to be variable and to occur over an extended period of time, adding complexity. Areas of intervention complexity that varied from study to study included the organizational levels targeted by the intervention, as some interventions focused only patients receiving care while others also included provider and clinic level components. Interactions of intervention components were found to be moderately to highly complex as most interventions involved interdisciplinary care across multiple facets of a given patient’s social, mental, and physical health with an explicit expectation that these aspects of care be coordinated and intertwined. In general, we found that the effect of most interventions would be impacted by individual level factors for both patients (eg, degree of SMI symptom severity) and providers (eg, experience and comfort with caring for target population). In contrast, we found a low level of complexity related to expectations of the skills of program participants at entry, as patients could receive care at whatever baseline function they had. Similarly, the staff delivering these interventions were generally felt to require minimal skills beyond their standard disciplinary training with the exception of education on the specific health and social needs of the target population and possibly around interdisciplinary collaboration.

Figure 7 Intervention Complexity Heat Map by Core Dimension of iCAT_SR^a^ a 1= lowest level complexity for dimension; 2 = moderate complexity; 3 = highest complexity

### Reported Effects of Included studies

While in keeping with an evidence map, we did not seek to synthesize the effects of interventions described in the included articles. However, in order to facilitate contextualization of the included literature, we report the findings of included articles as reported by the authors. Appendix E includes high-level summaries of the authors reported findings by included study with note of the study design, length of follow-up, and total number of participants when relevant. Reported findings suggest possible benefit in the areas of improved health outcomes,^28,37^ reduced emergency room/hospital utilization,^32,34,37^ increased primary care use,^45^ and reduced recidivism.^36,46^ In addition, reported findings suggest that integration of care across agencies within a larger system is complex and requires intentional efforts.^41,42,44^

## KEY QUESTION 2 What measures have been used to evaluate interventions among adults with experiences of homelessness or who are at high risk of experiencing homelessness and who have SMI to promote engagement in primary care?

### Key Points

- Included articles measured outcomes at the patient, clinic, or system level; patient level accounted for the majority of measured outcomes.
- Most common measures at the patient level were mental health status and substance use.
- Measures related to primary care integration included the number of primary care visits and the number of days between program enrollment and primary care visit.

### Detailed Findings

For KQ 2, we organize findings on the approaches to measuring the effect of interventions seeking to promote primary care engagement for adults with SMI and housing insecurity at 3 levels: patient level, clinic level, and system level (Figure 8). Of the 22 included articles (evaluating 15 studies), only 1 included outcomes at all 3 levels of analysis.^40^ Of the 5 articles that included outcomes at 2 levels, 4 examined both patient- and clinic-level outcomes^31,32,48,49^ and 1 examined both clinic- and system-level outcomes.^44^ The remaining 15 articles examined outcomes at only 1 level: 12 at the patient level^28–30,33,34,36–38,43,45–47^; 1 at the clinic level^35^; and 3 at the system level.^39,41,42^ Overall, most studies (17) evaluated outcomes at the patient level, and the fewest studies (5) at the system level. Appendix D summarizes the specific outcomes measures used for the included studies.

Figure 8 Outcome Measures Mapping

Outcomes evaluated at the patient level spanned a range of potentially overlapping domains that could be loosely categorized as mental and physical health; community functioning, community integration and quality of life; care utilization; patient experience and quality of care; and unmet needs/barriers to care. At the patient level, outcomes most commonly assessed mental health (6 studies) and substance use (5 studies) outcomes. Measures used to assess mental health included validated interviews and questionnaires such as the SF-36, Diagnostic Interview Schedule, and Brief Psychiatric Rating Scale.^28,33,34,37,40,45^ Substance abuse outcomes were measured using either the Addiction Severity Index or self-report.^28,32,34,37,40,45^ Other patient-level outcomes commonly assessed were involvement with the justice system (ie, incarcerations, arrests)^32,36,37,47^; housing-related outcomes (ie, self-reported number of days on the street or in shelter, achievement of independent housing)^28,33,34,40^; emergency department visits or hospitalizations^28,32,34,37,45,47^; and quality of life.^28,33,40^ Measures that specifically addressed primary care integration included the number of primary care visits^34,37^ and the number of days between program enrollment and primary care visit.^37^ Of the 11 outcomes evaluated at the clinic level, only the fidelity-to-care model was measured in more than 1 study.^40,49^ Of the 5 outcomes evaluated at the system level, only integration strategies^39–41^ and service linkage were measured in more than one study.^42,44^

### Summary of KQ 2 Findings

Overall, few consistent outcomes or outcome measures were used across studies. The only exception to this was the use of validated measures of mental health and substance abuse outcomes such as the Addiction Severity Index. Follow-up for outcome evaluation ranged from 3 weeks to 18 months, with the majority falling between 6 and 18 months. The concentration of outcome measures was greatest in the same area in which intervention strategies were found, specifically at the patient level.