# METHODS

We followed a standard protocol for this evidence mapping review, developed in collaboration with our operational partners and a technical expert panel. An evidence map “is a systematic search of a broad field to identify gaps in knowledge and/or future research needs that presents results in a user-friendly format, often a visual figure or graph, or a searchable database.”^21^ The protocol was developed prior to the conduct of the review, and was published online on the program website. There were not significant deviations after protocol publication. Each step was pilot-tested to train and calibrate study investigators. While there are no specific guidelines for reporting evidence maps, we followed the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines where applicable.^22^

## TOPIC DEVELOPMENT

This topic was requested by the National Center on Homelessness Among Veterans. Findings from this report will be relevant to the Veterans Health Administration (VHA) as it seeks to continue the provision of high-quality clinical care to the Veteran population with housing insecurity and SMI through the development of pilot programs to serve the primary care needs of this vulnerable population. The results of this project may also be relevant to individuals, health care providers, and other agencies seeking to improve the health and quality of life for individuals with housing insecurity and SMI.

### Conceptual Model

To guide this evidence map, we developed the conceptual model depicted in Figure 1. Patients with housing insecurity and SMI experience numerous barriers to engaging in primary care that occur at the patient, provider, and system levels. We recognize that engaging with primary care occurs across a spectrum that includes initial contact, establishing care, and care provision over time. To overcome barriers to engaging in primary care, interventions can employ strategies at these same 3 levels (patient, clinic, and system). Patient-level strategies focused on clinical techniques and delivery models that directly targeted the patient. Clinic-level strategies related to clinic- or provider-targeted approaches, including workforce development, staffing, and capacity-building activities. System-level strategies were activities to improve system integration for multi-sector coordination. For example, peer navigators can directly connect patients with care to help overcome challenges related to lack of transportation and social isolation. Care integration improves coordination among providers to help connect patients with the care they need. Finally, models such as collaborative care address system-level barriers, including care fragmentation, by implementing structural processes that support service alignment. Patient, provider, and system characteristics modify patients’ ability to engage with primary care and have an impact on the effect of primary care engagement on outcomes. When interventions effectively help patients to establish and maintain primary care, benefits are expected for patient health (eg, improvements in psychiatric symptoms), provider satisfaction, and the system (eg, reduced emergency department use). We also recognize that these interventions might lead to adverse outcomes, including patient dissatisfaction with care, oversights in medication management, and time burden for providers. The first KQ focuses on intervention strategies to improve primary care engagement of patients with housing insecurity and SMI. The second KQ explores the breadth of outcomes used to evaluate relevant interventions.

Figure 1 Conceptual Model

### Definitions

To guide the evidence mapping process, we established the following definitions in conjunction with our operational partners and technical expert panel.

- Experiences with homelessness is lacking a fixed, regular, and adequate night-time residence, including being unhoused or living in supervised shelters, supported housing, or places not intended for human habitation. Housing insecurity is being at risk for losing housing and lacking resources to obtain other permanent housing or receiving housing support services. However, because the terms “homeless” and “housing insecurity” are defining in multiple ways across the literature, we accepted any definition reported in the literature.
- Serious mental illness (SMI) is the presence of schizophrenia, other psychotic disorders, or bipolar disorder, consistent with the VA National Psychosis Registry (NPR). We acknowledge that there are multiple ways that SMI is defined. For example, some broader definitions of SMI include major depressive disorder (MDD) and posttraumatic stress disorder (PTSD). For the purposes of this evidence mapping review, we tracked which studies used the narrower (ie, NPR) definition and which used a broader definition, or which self-identified their targeted patient population as having SMI but did not provide enough information to determine whether it was the broader or narrower category.
- Primary care is a service that “provides long-term, patient-provider relationships, coordinates care across a spectrum of health services, educates, and offers disease prevention programs” to the general population.^23^
- Primary care engagement is the range of structured interactions between an individual patient and a primary care provider and/or primary care clinical team that has direct linkage to a prescribing primary care provider (eg, MD, DO, NP, PA). Specific engagement interactions can occur across a spectrum from initial contact (including patient identification and referral to primary care), establishment of a therapeutic relationship with a primary care clinic, and longitudinal patient-centered care delivery. In this context, a key component of engagement is the establishment of a relationship with a primary care clinic with the intent for regular, proactive contact for the purpose of managing health over time.

## SEARCH STRATEGY

We collaborated with an expert medical librarian to conduct a primary search of the literature from database inception to May 15, 2020, in MEDLINE® (via Ovid®), EMBASE (via Elsevier), and PsycINFO (via Ovid®). We used a combination of database-specific subject headings and keywords (eg, homelessness, primary care, veterans) to search titles and abstracts (Appendix A). No limits were placed on date or language. Case reports, editorials, letters, and conference abstracts were excluded from the search. We hand-searched previous systematic reviews conducted on this topic for potential inclusion.

## STUDY SELECTION

Studies identified through our primary search were classified independently by 2 investigators for relevance to the KQs based on our a priori eligibility criteria (Table 1), which were developed with the guidance of the technical expert panel. All citations classified for inclusion by at least 1 investigator were reviewed at the full-text level. The citations designated for exclusion by 1 investigator at the title-and-abstract level underwent screening by a second investigator. If both investigators agreed on exclusion, the study was excluded. All articles meeting eligibility criteria at full-text review were included for data abstraction. All results were tracked in both DistillerSR, a web-based data synthesis software program (Evidence Partners Inc., Manotick, ON, Canada), and EndNote^®^ reference management software (Clarivate).

Table 1 Study Eligibility Criteria

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | Ambulatory adults (≥18 years of age) who have had experiences of homelessness or those with housing insecurity [underlined: and] who have serious mental illness (SMI) as determined by meeting 1 of the following 3 criteria:; - Primary SMI, defined as at least a one-time diagnosis of schizophrenia, other psychotic disorder, or bipolar disorder (as per VA NPR; see expanded definition above on page 13); - Secondary SMI, defined as the above diagnoses [underlined: plus] major depressive disorder (MDD) or posttraumatic stress disorder (PTSD); - The population was explicitly labeled as SMI by the study authors even if the operationalized definition of SMI is different than the above 2 categories (eg, could be labeled as severe and persistent mental illness (SPMI)) | - Children, teens; - People with substance use or depression not specified as MDD as the only diagnosed mental health condition; - <75% adult population with SMI; - Interventions that are not targeted toward homeless populations, or are targeted only to those with housing insecurity but who no longer need housing services; - Mixed populations of homeless and nonhomeless without subgroup analysis
Interventions | Interventions designed to promote structured interaction with a prescribing primary care clinician or with a clinical team member who has a direct linkage, or facilitates linkage, to a prescribing primary care clinician [underlined: and] that meet 1 of the following 3 criteria:; - Intervention is specifically targeted to patients with housing insecurity and SMI; - Intervention is targeted to patients with housing insecurity, of whom at least 75% have SMI or diagnoses consistent with SMI; - Intervention is targeted to patients with housing insecurity and includes a subgroup analysis with outcomes reported separately for the group of interest | - Interventions that do not include a prescribing primary care healthcare clinician (eg, PCP, NP, PA), which has no direct linkage, or which do not facilitate linkage to one; - Interventions that involve a social worker or mental health provider without direct connection to a primary care clinical staff member
Comparators | Any comparator (eg, usual care, active comparator) or no comparator | Not applicable
Outcomes* | Any | Not applicable
Timing | Any | Not applicable
Setting | Any (eg, clinical, housing services, criminal justice system) | Not applicable
Study designs^a^ | - EPOC: randomized trials, nonrandomized trials, controlled before-after studies, interrupted time series^a^; - Observational: cohort, organizational case study, program evaluation; - Relevant systematic reviews or patient-level meta-analyses must have search strategy, eligibility criteria, and analysis/synthesis plan; - Qualitative studies must include description of intervention strategy and/or components | - Not an intervention evaluation study (eg, editorial, nonsystematic review, letter to the editor, conference abstract); - Clinical guidelines; - Protocol only; - Individual patient case study
Language | Any | Not applicable
Countries | OECD^b^ | Non-OECD
Years | Any | Not applicable
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

a Cochrane EPOC criteria identify study designs optimal for evaluation of health system interventions^24^

b OECD = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

Abbreviations: EPOC=Effective Practice and Organisation of Care; MDD=major depressive disorder; NP=nurse practitioner; PA=physician assistant; PCP=primary care physician; PTSD=posttraumatic stress disorder; SMI=serious mental illness; SPMI=severe and persistent mental illness

## DATA ABSTRACTION

Data from included studies were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. We treated multiple reports from a single study as a single data point, prioritizing results based on the most complete and appropriately analyzed data. We approached data abstraction in 2 phases.

First, data elements such as descriptors to assess applicability, high-level intervention details, and outcomes were abstracted. Key characteristics abstracted included patient descriptors (eg, age, sex, race), intervention characteristics (eg, entry point to care, engagement methods, provider type), comparator (if any), and outcomes. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors. Key features relevant to applicability included the match between the sample and target populations (eg, age, Veteran status).

Second, a subgroup of the larger team (MSB, CD, JRD, KMG) abstracted specific strategies used by each intervention or program. An initial list of potential strategies was drawn from previous reviews of interventions linking primary care to patients with experiences of homelessness.^14,15^ The list of potential strategies was revised collaboratively by the subgroup of investigators after abstracting an initial 2 citations. The intervention strategies for the rest of the included studies were abstracted independently by 2 investigators and then reconciled for final determination. This group met regularly during this second-level abstraction to discuss any additional changes needed for the intervention strategies list.

For details of study characteristics, see Appendix B. Appendix C presents details of the intervention characteristics. Appendix D lists outcome measures, and Appendix E shows reported findings by included study. Appendix F lists excluded studies and the reason for exclusion.

## QUALITY ASSESSMENT

As this is an evidence mapping review, we did not assess the methodological quality of individual studies.^21^

## DATA SYNTHESIS

We summarized the literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention. Data were summarized narratively. Data presentations include tabular and graphical formats, as appropriate, to convey key features of the literature.

In order to systematically characterize the complexity of included interventions and programs, we used the intervention Complexity Assessment Tool for Systematic Reviews (iCAT_SR).^25^ Two investigators (KMG, MSB) applied the 10 iCAT_SR dimensions and assessment criteria to an initial 4 studies to establish an approach to application in the context of this mapping project. Then, the iCAT_SR was applied to the remaining included studies by 1 investigator and over-read by a second (Appendix G).

Next, we sought to determine an intervention’s degree of integration with primary care. While we are aware of existing frameworks that allow for the categorization of interventions along a continuum of integration^26^ or integrated mental health, such as the Integrated Practice Assessment Tool (IPAT),^27^ we were unable to apply existing tools directly because of insufficient information provided by individual studies. Therefore, we identified the following individual key elements of integration based on such tools and identified the presence or absence of each element across the included studies:

(1) Standard referral: nonspecific referral pathways linking patients to primary care without evidence of clear interactive communication
(2) Enhanced referral: established relationships with primary care providers who are not an embedded part of the intervention, but with whom there is some form of interactive communication across disciplines that can be activated when needed
(3) Co-location: primary care is co-located in same physical space as other disciplines working with targeted patient population (note this can occur with or without interdisciplinary care planning)
(4) Interdisciplinary care planning: evidence of regular interdisciplinary collaboration around the planning of care for individual patients (note that this can occur with or without co-location of disciplines)

Our analysis is presented as a broad literature map without synthesis of the results across studies or quality of individual studies, or the strength of evidence for the KQs.

## RATING THE BODY OF EVIDENCE

In keeping with established methods for evidence mapping reviews, we did not grade the strength of evidence for each KQ.^21^

## PEER REVIEW

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix H