# INTRODUCTION

Adults with experiences of homelessness, both those who have been homeless and those with housing insecurity, are more likely to suffer from higher rates of chronic illness and early mortality compared with those who are not homeless.^1–3^ The homeless population also experiences a higher mental health burden than the general population; about 20-25% of people who experience homelessness in the United States also have diagnosed serious mental illness (SMI).^4,5^ Moreover, Veterans who experience homelessness and have used the emergency department have a 3.4-fold higher likelihood of being diagnosed with schizophrenia.^6^ The VA National Psychosis Registry defines SMI as the presence of schizophrenia, other psychotic disorders, or bipolar disorder. Mental and behavioral health disorders threaten household stability, which, in turn, leads to poor community integration and treatment dropout.^7^ Hence, both homelessness and mental illness are key vulnerabilities that undermine health and access to health care for this population. Individuals with experiences of homelessness and SMI would benefit greatly from medical care to help manage their chronic health needs, yet the underlying context of both homelessness and SMI restrict their engagement in traditional, clinic-based primary care. For example, stigma in the health system,^8^ lack of transportation, and prioritizing basic needs above health concerns limit their ability to obtain primary health care.^9^ Further, the risks of homelessness and SMI together likely amplify barriers to health care. For example, SMI increases housing insecurity,^10^ and housing insecurity impedes engagement in health care,^11,12^ which in turn increases SMI symptoms. As a result, these individuals receive less preventive care and chronic disease management and often receive the majority of their health care in acute care settings such as emergency departments.^6^

Thoughtful interventions have been developed to directly address some of the barriers to engaging in primary care for populations with housing instability and populations with SMI.^13^ However, despite the high prevalence of SMI among people who experience homelessness, most interventions tailored to this population currently focus on either SMI or homelessness and few efforts have been developed to address both vulnerabilities and the intersection between the two.^14,15^ The few studies that have sought to improve health care engagement to meet the complex health and social needs related to both homelessness and SMI have focused broadly on collaborative and patient-centered medical home models tailored for this population to address social determinants of health.^15–17^ Research shows that these interventions can improve continuity of care, use of primary and mental health care,^16–18^ and housing outcomes.^19,20^ While this research is promising, to date there have been no systematic examinations of the breadth of the literature about interventions that attempt to improve engagement in care for populations with intersecting needs related to SMI and homelessness.

For health systems to better meet the health care needs of this complex population, it is critical to learn about the types of interventions and strategies that have been evaluated to better connect patients with housing insecurity and SMI to primary care, and which outcomes they evaluated. In this evidence map, we systematically examine the literature and provide an overview of the quantity and distribution of intervention types and components that were assessed to improve engagement in primary care for individuals with housing insecurity and SMI. The overarching goal is to provide a better understanding of the breadth of intervention models that promote primary care engagement among individuals with experiences of homelessness or who are at high risk of experiencing homelessness and who have a history of SMI.

The Key Questions (KQs) for this evidence map were:

KQ 1 What intervention strategies have been studied among adults with experiences of homelessness or who are at high risk of experiencing homelessness and who have serious mental illness (SMI) to promote engagement in primary care?
KQ 2 What measures have been used to evaluate interventions among adults with experiences of homelessness or who are at high risk of experiencing homelessness and who have SMI to promote engagement in primary care?