# APPENDIX H PEER REVIEW COMMENTS AND RESPONSE TABLE

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes
Is there any indication of bias in our synthesis of the evidence? | 1 | No
Is there any indication of bias in our synthesis of the evidence? | 2 | No
Is there any indication of bias in our synthesis of the evidence? | 3 | No
Is there any indication of bias in our synthesis of the evidence? | 4 | No
Is there any indication of bias in our synthesis of the evidence? | 5 | No
Is there any indication of bias in our synthesis of the evidence? | 6 | No
Is there any indication of bias in our synthesis of the evidence? | 7 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 1 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 2 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 3 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 4 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 5 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 6 | No
Are there any [underlined: published] or [underlined: unpublished]; studies that we may have overlooked? | 7 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | I think the report clearly demonstrates that this is not a well studied area despite the high morbidity and mortality in this population. I think these are two populations that commonly suffer from healthcare inequities for many reasons. The meager evidence base suggests that similar gaps may also exist in research. People with serious mental illness are disproportionately represented in the homeless population and more effort should be devoted to this type of research.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | General feedback: the presentation of results, switching between categories of findings and “most common” strategies, was confusing and make it a bit difficult to know what to value in terms of findings. | We appreciate this source of confusion and have addressed as described below.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Presentation of characteristics of studies in narrative form was a bit difficult to follow and would be better done via a Table. | We agree and have added an evidence profile table.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | The Executive Summary Methods left out key information related to the process of selecting studies for inclusion. More specific feedback:; p.8 - Can you include a sentence to explain the process by which 4,000+ articles were excluded? This was not clear based on your previous Methods section. | We have clarified in executive summary method that a standard dual-screener approach was used to exclude ineligible citations. In keeping with current standards, we have left additional detail in the main body of the report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.8 – 22 studies were included in your review sample yet the total number of strategies here is more than 22. Similarly, your previous section mentions that there are 15 unique interventions but this mentions 22 intervention strategies. Can you mention that some studies had more than one level of focus or otherwise clarify this seeming lack of continuity? | We understand this confusion. We have added detail to clarify that each individual study could have used multiple intervention strategies at multiple levels.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.8 - Another point of clarification - did you approach focus only on the primary strategy within each study, or the primary strategy at each level within a study (if one study could be counted multiply at patient/clinic/system levels), or could a single study have multiple strategies which were recorded? Tis would be useful to clarify, as these sentences about the “most common” strategies at the clinic and systems level are not clear to the extent that they are a comprehensive list of ALL mentioned strategies or only the most commonly-mentioned strategies, given the relatively small number of studies in each of these groups. | We appreciate this confusion and have removed the phrase “most common” from the report. Indeed, we identified all mentioned strategies across all included studies. We now use the phrase “most frequently described” to indicate that the relevant strategy was one that was reported the most across all included studies.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p. 9 – you mention one outcome of “reduced recidivism” as outcome of interest, but do not mention what action is being reduced – use of high-intensity MH services? Use of ED services? Inpatient care? It would be good to clarify. | We have revised this to read: “Reduced criminal recidivism”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.21-22: can a table be created to summarize the characteristics of the studies included in this review. The narrative provides a lot of numbers describing different characteristics of included studies which tend to blend together and would be better presented as a table. | We agree. As noted above, we have added an evidence profile table for clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.23 – you state that you “identified 22 patient-level strategies across 6 groups; 4 clinic-level intervention strategies across 3 groups…” etc. The term “group” here is a bit confusing, as I was not clear if you meant this to reflect different studies, subpopulations which might be represented across different studies, or populations within the same study which were compared. Is there a better term to use here instead of “group”? | We agree and have relabeled this section. We now refer to intervention strategies as those activities conducted as part of a study to effect a benefit for the target population. Strategies were grouped by domain, and domains were categorized by patient/clinic/system levels.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.23 – you mention the “most common patient-level strategies…” this phrasing is a bit imprecise and makes interpretation of this section a bit confusing. Does this mean that less-common strategies are not reported in this analysis? Also, the presentation approach which mentions the 5 categories into which all patient-level strategies will be classified, followed by a presentation of the “most common” strategies which span multiple categories, is further confusing. This section could be improved by clarifying that the 5 “groups” reflect the categories which patient-level intervention strategies were organized into and by dropping any mention of “most common” strategies unless this can be more clearly quantified (by number of studies?). This shift from the categories of interventions to types of interventions in a manner that does not go through the categories of interventions is very confusing. Perhaps some subheadings would improve this section, by dividing the discussion into categories of strategies rather than jumping between them? | As noted above, we have removed the phrase “most common” to categorize strategies and are using “most frequently described”. We have also added the # of studies using listed strategies within the text for clarity
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.27 – similar to the section on patient-level strategies, the section on clinic-level strategies would benefit from more organization/structure. I recommend either creating subheadings which reflect the categories of strategies or moving in a more structured way through a presentation of the categories and the strategies which fall in each category. A presentation of “most common strategies” is confusing given the current lack of clear structure in this narrative section. | We have also restructured the clinic and systemlevel strategy sections as described above for clarity and consistency.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.30 – similar feedback to that related to p. 23 and p. 30 – more clear structure in this narrative section will help avoid confusion related to strategies, categories, and “most common” strategies. | We have also restructured the clinic and systemlevel strategy sections as described above for clarity and consistency.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.38 – this presentation of detailed findings was very clear and well-written. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | P.39 – Figure 7: this provided more clear information on findings, using numbers to reflect measures at different levels. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | p.41 – the presentation focusing on “most common” strategies without any mention of the categories of strategies from earlier in the report makes me think that it may be more useful to focus on a count of the number of studies that used each strategy as well as a presentation which reflects % of studies that reflected each strategy –this could provide more concrete framing of how widespread the “common” studies are within the | We appreciate this suggestion and have added quantitative data to support and clarify these assertions.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 6 line 20- the adjective “knowledgeable” appears to be applied to “clinical setting”, which seems off. “context of a knowledgeable and familiar clinical setting” | We have reworded this sentence to read “in the context of a population-tailored clinical setting”.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 6 line27; “Thoughtful interventions exist which focus on collaborations with either SMI or homelessness..”; Are words missing? This appears to refer to collaborations between health/ social conditions, when it is assumed to be intended to refer to professionals collaborating. | We have reworded this sentence to read: “Previously developed interventions have focused on collaborations between primary care and either persons with SMI or persons experiencing homelessness, but few have targeted both populations simultaneously.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 11 line 22 “Disorientation” is not a common symptom among those with most types of SMI. Disorientation would be more common in dementia or delirium. The phrase “disorientation due to SMI symptoms” would itself perpetuate the next issue in the list - “stigma in the health system”. | We appreciate this point and have removed this phrase from the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 12 line 27 The concept of protocol registration is introduced without being defined. It is not entirely clear whether | We have removed the term ‘registration’ and clarified that the protocol was published the program website.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | publishing the protocol online is the registration process or something else.; Page 13 lines 54-56- Most VA readers will lack a minimal understanding of what is included in the National Psychosis Registry (NPR) . Probably zero non-VA readers will know this. The acknowledgement of variation in SMI definitions is noted and appreciated. Clarification is on whether NPR includes some non-psychotic psychiatric diagnoses. I believe that it does, but a leader is likely to assume from the name of the registry that it only includes psychotic disorder. There is no definition of SMI known to me that includes only psychotic disorders. Non-psychotic bipolar disorder would be a good example of an SMI that would be included in nearly every SMI definition. | We have added that The VA National Psychosis Registry defines SMI as the presence of schizophrenia, other psychotic disorders, or bipolar disorder to the Introduction section of the executive summary, the Introduction section of the full report, and the Definitions section of the Methods.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 13 Conceptual model is very clear and well-done generally. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 15 The definition of SMI here makes no mention of; National Psychosis Registry, so it is unclear if there is a different definition than on page 13. | We have added language to Table 1 to indicate that we used the same definitions as outlined on page 13.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 16 EPOC is defined in terms of what the letters stand for, but the association with these letters and types of studies has not been explained. | We have clarified in a foot note for Table 1: “Cochrane EPOC criteria identify study designs optimal for evaluation of health system interventions” and have provided a citation for addition reference.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 21 line 28-29 “mental health comorbidities” - comorbid to what? It seems SMI is your primary condition, so it is not clear to what comorbidities refers | We agree that this is confusing and have removed this phrase.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 23 the graphic is very nice. Could it possibly be expanded to include names of strategies and possibly sub strategies? | Thank you. Figure 4 is intended to provide a highlevel overview of the way the subsequent section is organized. Additional details about the names of the strategies and domain are listed in subsequent tables. Thus, we have relabeled Figure 4 as a “Framework of Multi-Level Intervention Strategies” to clarify the figure intent.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 24 Assertive community treatment is also a clinic and possibly system level intervention. I am making a note here in case ACT is not also classified this way later in the paper. | We agree that Assertive community treatment could have been classified in multiple ways. Because we were identifying strategy levels based on the targeted effect, we elected to categorize as patientlevel. We have added a statement in the limitations that these could have been categorized differently.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 32 I am sorry if I missed it, but have you all talked about the relationship of having housing with engagement with primary care. The relationship was discussed in the intro, and I understand the paper is on homeless people. Still, one would expect homelessness to be dynamic. Getting folks housing surely increases engagement with healthcare, right? Housing First is a big intervention in this field. I wonder if you all might want to look at healthcare engagement in these trials. Apologize if I missed this. | We agree that the experience of homelessness is a dynamic process and has the potential to impact an individual’s ability to engage with healthcare. In particular, we explored an individual’s ability to engage with primary health care. See Figure 5 for how we considered intervention approaches to engage with primary care. (See also Whisler A, Dosani N, To MJ, O’Brien K, Young S, and Hwang SW. The effect of a Housing First intervention on primary care retention among homeless individuals with mental illness. PLoS One. 2021;16:e0246859. )
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | The paper would generally benefit from further review by a medical editor. There are some places where the writing could be made more clear. | We have worked with our medical editor to improve the clarity of the writing.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | I will upload the ESP with comments embedded in the PDF.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Figure 4. Multi-level Intervention Strategies; Not sure of point of this figure. Maybe would be easier to interpret if the strategies were listed and the corresponding table number were embedded into the three levels | Thank you for this suggestion. As noted above, we have reworked this figure for clarity and to optimize added value.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Patient-Level Intervention Strategies; 5 groups, but 6 patient-level strategies…. is there one missing? Might be helpful to use the same language. | We have corrected this typo.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Pg 23 Row 56; Are these now describing sub-strategies? | As noted above, we have relabeled each level for clarity. This line is referring to strategies.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Pg 24 row 22 By “strategies” here, does this mean substrategies? | As noted above, we have relabeled each level for clarity. This line is referring to strategies.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Table 2. Patient-Level Intervention Strategies; Evidence-based patient interactions; Can call this provider-patient communication techniques? wonder if CBT, ACT, counseling and family therapy should be in the left column preceded by “Other: xxx” with the definition in this column. | Thank you, we have renamed this category “Patientprovider communication techniques”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Table 2. Patient-Level Intervention Strategies; Assertive outreach; IS this the same as ACT above? | Thank you for this suggestion. We agree that it would generally be assumed that Assertive community treatment (ACT) would include assertive outreach. Although a study could potentially have assertive outreach without including other tenets of ACT so we have left as separate.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Table 2. Patient-Level Intervention Strategies; Wonder if middle column can be moved to left preceded by “Other: xxx” so it can be defined in the middle column, as column heading specifies. What is, for example, “reasonable”? | We have shifted those strategies previously in the middle column to the left column and added appropriate definitions as requested.; The term “reasonable costs” came directly from the cited study which used the full phrase “provides services at reasonable costs.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Table 3. Clinic-Level Intervention Strategies; Medical scribes; Not sure why this is here? Not mentioned in text as part of logic model and not in any study | We identified an initial collection of strategies based on existing systematic reviews of similar types of interventions. Though we did not find each a priori identified strategy in the included studies, we kept them in our report so as to describe the breadth of potential strategies as fitting an evidence map.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Table 4. Clinic Level Staffing by Discipline; Pharmacist; Does this mean “none”? | Yes. We have reworded this row to “none” from “not applicable”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Intervention Complexity (Pg 35); also interesting that organization level expected to be quite low, maybe in terms of shared EHR, data, outcomes, etc? | This core dimension refers to the number of organizational categories to which the study intervention was directed (ie, individuals, groups or teams of individuals, systems). So the lack of complexity across studies in this dimension reflects that most interventions targeted individuals vs across all levels.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Summary of KQ 2 Findings (pg 39); I could see MH and SUD outcomes obtained at baseline. Was the goal for these studies to improve MH/SUD outcomes as a byproduct of PC engagement? | The primary outcome or objective of included studies varied. Most were not primarily aiming to improve primary care engagement.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Limitations; Study Quality and Design (pg 43); This limitation is important. would include this in the executive summary. I think I only saw that PC engagement was not endpoint for many studies. | We agree and have added this point to the executive summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | This evidence synthesis compiles the literature on primary care utilization and engagement among adults with homeless experiences and serious mental illness. The authors are to be commended for the tremendous effort put into this report; they thoroughly synthesized the literature and aimed to use key findings to inform VA’s efforts to develop programs to enhance primary care use among Veterans with homeless experiences and serious mental illness. The report is clear and well-written. I have a variety of comments below. Some overarching feedback, buried in these comments, includes the following: | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | a) The report could benefit from more clarity about the definition of homelessness / housing insecurity. I would recommend using the term adults with homeless experiences, and defining up front that this includes individuals who have experienced homelessness and those with housing insecurity | We have changed the first sentence of the introduction in the executive summary and main report to use this language and stated this definition. In addition, we have changed the patient to be person-first throughout. We have also changed the title accordingly.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | b) It would help to define this population as a population with “two vulnerabilities;” this would clarify some key points made in the report – that perhaps could be highlighted – that systems of care tailored to this population with two vulnerabilities currently focus on homelessness or serious mental illness, and few efforts have been made to address both vulnerabilities and the intersection between them | Thank you for this point. We appreciate this framing and have added language to the Introduction in Executive Summary and the main Introduction.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | c) In thinking about evaluation measures for interventions (KQ2), a key problem in evaluating in the literature is the dearth of measures that are validated for persons with homelessness, much less persons with homeless experiences and SMI. | This is an important point which we have added to the discussion of the limitations of the current literature (see page X).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Acknowledgments; ○ The National Center on Homelessness among Veterans typically does not capitalize the “A” in among | Thank you. We have corrected this typo.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Technical Expert Panel; ○ Corrections to my name; ○ My degrees are MD, MPH (VA was accidentally included); ○ My title can be Physician and Health Services Researcher | Thank you, we have made these changes.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Executive summary; ○ I would define SMI the first time it is mentioned in the executive summary. Can be interpreted in many ways as a diagnostic group.; ○ Minor typos:; ▪ Page 9, line 38, remove comma between assessed and included; ▪ Page 9, line 56, there needs to be a space between over and time; ▪ Page 9, line 56 missing word – Third, there IS a need to… | We have added the VPR definition of SMI to the executive summary introduction.; The noted typos have been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Introduction; ○ I would like to see clear definitions of homelessness and SMI up front – these are presented later (in the methods), but anyway to move them up to the introduction would improve the document | We have added greater definition for each these terms at the beginning of the introduction.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Page 11, line 22 uses the word “disorientation” due to SMI symptoms – I’m not sure what that means. Persons with psychotic disorders are not disoriented. They may be conceptually disorganized. | We have removed this word.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Another key point for the introduction is that stigma often results in patients with SMI’s medical complaints being dismissed or thought of as psychiatric in nature | We agree with this point and have added a few citations to substantiate the importance of stigma for individuals with SMI and homelessness. If the reviewer has a specific reference regarding the dismissal of medical complaints, we would be happy to review and add it.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Methods; ○ The conceptual framework might benefit from more population-specific examples of moderators and outcomes. For example, an important patient characteristic might be housing status. Important patient outcomes might be housing outcomes, psychiatric symptoms. | We agree with this suggestion and have provided more population specific examples of moderators and outcomes. We have modified the wording in the description of the conceptual model and better defined the 3 levels.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ I am struggling with the inclusion criteria of currently homeless – in the literature this generally includes persons who are engaged in housing services, particularly within VA. Homelessness is a transient state that individuals vacillate in and out of. We generally talk about persons with homeless experiences to use person centered language. | We have reworded this criteria to “Ambulatory adults (≥18 years of age) who have had experiences of homelessness or those with housing insecurity”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - KQ1; ○ Housing First is mentioned for the first time on p.24, line 8. I would define this as “permanent housing with supportive services, including linkages to nonmandated health services.” | We have reworded this sentence to the following: “This included, but was not limited, to studies that incorporated the “Housing First” program model, which prioritizes permanent, stable housing with supportive services, including linkages to nonmandated health services”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ It’s hard to conceptualize what “crisis intervention” looks like in terms of primary care engagement (p. 24, lin3 19) → this term generally does not describe a response to acute concerns that can be managed in primary care settings | We appreciate this question. It is important to note that we identified all intervention strategies regardless of whether or not they were specifically relevant to primary care as they were part of an intervention that included primary care engagement. We have added the following sentence to the beginning of the intervention strategies results section:” Intervention strategies identified were not restricted to those pertaining to primary care engagement.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Table 4:; ▪ The definition of psychiatrist probably should not say “psychiatrist.” Perhaps - Physicians trained in psychiatry; psychiatric/menta health nurse practitioners. Note that psychiatrists do fall under behavioral health as well. | We have reworded as suggested.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ Is there a reason not to define nursing? Is this RN level care? NPs? | We have added the following definition: “Nurses without prescribing privileges of any training level or not otherwise specified”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ Primary care provider should parallel the psychiatrist definition. Perhaps Physicians trained in primary care, primary care nurse practitioners/physician assistants | We have reworded this definition as suggested.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ I am not sure what social work (nonspecified as LCSW) means. Is this referring to social workers but you don’t know whether or not they are licensed? | LCSW refers to a specific licensure for individuals with a masters of social work who have also undergone extensive training and certification to diagnose and treat mental health disorders using psychotherapy approaches.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Clinical and policy implications; ○ Page 43 – line 17: rename the Center the National Center on Homelessness among Veterans | We have renamed as recommended.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ The VA has tested PCMH models for Veterans with homelessness (HPACT) and Veterans with SMI (SMI-PACT)
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ There are two contrasting approaches in thinking about PC engagement for persons with SMI in these two models. The HPACT model tailors care for people with homelessness, many of whom have mental health problems (including SMI), but it is ultimately a primary care setting. SMI PACT actually is distinct model, a PACT for people with SMI, but it is intentionally a model for people with SMI who have relatively stable mental illness that can be managed in primary care settings, with psychiatric/mental health consultation only | Thank you for this point—we have expanded our discussion of these services and added information about supported employment and the MHICM in the clinical implications section.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ There is a larger notion in terms of clinical implications that I would love to see mentioned somewhere. For homeless people with SMI, there is the idea that primary care services can be embedded in mental health settings (people with SMI may be most engaged in MH) or there is the distinct idea that PC and MH should be integrated in a PC setting (though at VA and in many other settings, PCMHI is not wellsuited for persons with SMI, so this would require further tailoring). | While we agree with the reviewer’s recognition of the important clinical implications here, because this is an evidence map and not a systematic review – we are unable to draw specific conclusions to support specific recommendations for clinical care delivery.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ▪ Relevant in the VA context are programs like MHICM, which serve patients with SMI exclusively, but often do not have embedded PC services | We mentioned this point in the Clinical Implications section
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Limitations; ○ Page 43, line 39 – the authors describe “connecting patients with SMI to primary care” – did they intend to use homelessness somewhere in this sentence also? | Yes, we have added this language.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Page 43, line 44 – the word housing insecurity is used, not homelessness. I mentioned this earlier but I think I would use an all-encompassing definition up front of homeless experiences that includes persons at risk for becoming homeless to clean up the nomenclature throughout | We agree and have changed this language throughout.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ The discussion about outcome measures is interesting – to me, a clear limitation of the body of literature being synthesized is that use of measures that are not validated or even intended to be used by this population with two core vulnerabilities | We agree with this point and have added this to the limitation section as follows: “Finally, no outcome measures were clearly validated or designed for the specific patient population of those with experiences of homelessness.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Page 44, line 51 – consider changing to …clinical setting (two were in VA)… | This has been corrected as recommended.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Though the VA is an integrated health and social service system, the challenge would be integrate across its health and social service sectors, which can be challenging | We agree with this point and have added language and a citation to support fragmented service delivery across the health and social sectors in VA in the Generalizability to VA section of the report
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Table 9; ○ See earlier comments about concerns using the words housing insecurity instead of homelessness | This language has been corrected throughout.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Not sure what is meant by Patients with SMI and housing insecurity with additional co-occurring chronic health conditions – does this refer to strategies to address specific chronic health conditions, e.g., diabetes? Chronic medical illness is highly prevalent – and the norm – in this population of adults with two vulnerabilities | This sentence has been removed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ Page 46, line 16 – primary care teamS differ; ○ What spectrum is being referred to in line 27 of page 46? | Typo corrected; We have clarified this sentence to read: “….across the spectrum of engagement from initial visit to longitudinal care”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | - Conclusions; ○ See earlier comments about use of housing insecurity | This language has been changed throughout.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | ○ When commenting on the unique position of VA, I would also note that the VA is the nation’s largest provider of SMI services | Thank you, we have added “As one of the nation’s largest integrated heath care providers…” to the Conclusions of the report and cited Zeiss AM and Karlin BE. Integrating Mental Health and Primary Care Services in the Department of Veterans Affairs Health Care System. J. Clin. Psychol. Med. Settings. 2008;15:73–78.19104957
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | Overall a very well constructed and helpful summary. There is clearly a need for more research and better identification/measurement of primary care engagement and an understanding of longer term impacts. An additional need is exploration of engagement strategies for individuals with experiences of homelessness. The majority of studies examined did not appear to include individuals with a history of homelessness. VA tracks Veterans in homeless programs after they have been successfully housed recognizing that there are persisting risks and barriers to care and elevated morbidity and mortality. There may be differences in approach needed for “street homeless” vs. those with housing instability vs. those with experiences of homelessness but all likely require targeted enhancement strategies. | Thank you.; The recognition of different populations of persons with experiences of homelessness is an important one. We did not identify any studies focused on individuals with a history of homelessness only or studies that examined how experience of homelessness (ie, street homelessness vs. housing instability) moderated the intervention effect. We have cited this as a limitation of the current literature and a need for future research. “For example, experience of homelessness (ie, street homeless vs. housing instability) could moderate intervention effects, but few studies considered patient-level moderators.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | On page 43, line 17 the sentence reads: “For example, VA offers services through the National Center on Homelessness, has tested a patient-centered medical home model for Veterans with SMI, …” This didn’t read correctly/make sense to me and I wasn’t sure if what was being referenced was SMI-PACTs or HPACTs. Also, technically,, the NCHAV doesn’t offer services directly. Services may be developed/piloted/tested via the NCHAV but core offerings such as Homeless Patient Aligned Care Teams (HPACTs) are not under the NCHAV. | Thank you for this clarification. We have revised this sentence to read: “For example, the VA Homeless Programs Office has developed and implemented designed primary care teams to provide care specifically for patients with experiences of homelessness(H-PACT), the VA and has also tested a patient-centered medical home model for Veterans with SMI (SMI-PACT),…”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | Page 9 line 14 - about 20% of people who experience homelessness in the United States also have diagnosed serious mental illness (SMI) - 20% seems low unless it is “diagnosed” and general population including youth/children | We identified several sources that provided prevalence estimates within this range. Our original reference was from the National Alliance on Mental Illness (2019) and we added two other references: National Coalition for the Homeless. Mental Illness and Homelessness. Available at: www.nationalhomeless.org/factsheets/Mental_Illness.pdf. Accessed March 22, 2021. 2009. and; Tsai J, Mares AS, and Rosenheck RA. Do homeless veterans have the same needs and outcomes as non-veterans? Mil. Med. 2012;177:27–31.22338975
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | Page 46 Line 17 - VA offers services through the National Center on Homelessness - what services are you referring to? We at the Center don’t offer direct Veteran care services rather we engage in research, education, model development, and being a resource center. The Homeless Programs Office oversees homeless programming. If this service is what this sentence is referring to, then would recommend replacing NCHAV with HPO. NCHAV is under HPO. | We have reworded this section as noted above.